# Results

## Rats

### Two-week Dermal Study

All rats survived to the end of the study (Table 2). The final mean body weights and body weight gains of all dosed groups were similar to those of the vehicle control groups. There were no clinical findings related to o-chloropyridine administration.

Table 2 Survival and Body Weights of Rats in the Two-week Dermal Study of o-Chloropyridine^a^

Dose (mg/kg) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 5/5 | 90 ± 3 | 157 ± 6 | 68 ± 3
6.25 | 5/5 | 88 ± 4 | 159 ± 6 | 71 ± 3 | 101
12.5 | 5/5 | 87 ± 3 | 157 ± 4 | 70 ± 2 | 100
25 | 5/5 | 85 ± 3 | 153 ± 3 | 68 ± 2 | 97
50 | 5/5 | 88 ± 2 | 158 ± 5 | 71 ± 3 | 101
100 | 5/5 | 87 ± 3 | 158 ± 4 | 71 ± 2 | 101
Female
0 | 5/5 | 82 ± 3 | 120 ± 2 | 39 ± 2
6.25 | 5/5 | 80 ± 2 | 121 ± 1 | 41 ± 2 | 101
12.5 | 5/5 | 81 ± 3 | 120 ± 3 | 40 ± 1 | 100
25 | 5/5 | 81 ± 4 | 122 ± 4 | 41 ± 2 | 102
50 | 5/5 | 80 ± 2 | 120 ± 2 | 40 ± 2 | 100
100 | 5/5 | 80 ± 2 | 120 ± 2 | 40 ± 1 | 100

^a^ Weights and weight changes are given as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test.

^b^ Number of animals surviving at 17 days/number initially in group.

The absolute and relative liver weights of 50 (absolute, 10.6%) and 100 mg/kg (absolute, 9.6%) males were significantly greater than those of the vehicle controls (Table 3 and Table C-1). Absolute and relative organ weights of all dosed groups of females were similar to those of the vehicle controls (Table C-1). No gross or microscopic lesions were considered related to o-chloropyridine administration.

Table 3 Liver Weights and Liver-Weight-to-Body-Weight Ratios for Male Rats in the Two-week Dermal Study of o-Chloropyridine^a^

| Vehicle Control | 6.25 mg/kg | 12.5 mg/kg | 25 mg/kg | 50 mg/kg | 100 mg/kg
n | 5 | 5 | 5 | 5 | 5 | 5
Necropsy body wt | 157 ± 6 | 159 ± 6 | 157 ± 4 | 153 ± 3 | 158 ± 5 | 158 ± 4
Liver
Absolute | 8.02 ± 0.28 | 8.13 ± 0.18 | 8.25 ± 0.23 | 8.03 ± 0.16 | 8.87 ± 0.35* | 8.79 ± 0.11*
Relative | 51.083 ± 0.188 | 51.251 ± 0.857 | 52.473 ± 1.018 | 52.428 ± 0.422 | 55.961 ± 0.567** | 55.732 ± 0.777**

* Significantly different (P ≤ 0.05) from the vehicle control group by Williams’ test.

** P ≤ 0.01.

^a^ Liver weights (absolute weights) and body weights are given in grams; liver-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Exposure concentration selection rationale: Exposure concentrations in the 3-month drinking water study were selected for comparison to the 3-month pyridine study results.^33^

### Three-month Drinking Water Study

All rats survived to the end of the study (Table 4). Final mean body weights and body weight gains of male and female rats exposed to 1,000 ppm were significantly less than those of the controls (Table 4 and Figure 2). Water consumption was lower in the 1,000 ppm groups, compared to controls, particularly during week 1 of the study. In male and female rats, water consumption in the 1,000 ppm groups was approximately half that of controls in the first week, increasing in week 2. By week 14, water consumption by female rats had completely recovered while water consumption by male rats was only slightly less than that of controls (Table 4, Table G-1, and Table G-2). Drinking water concentrations of 10, 30, 100, 300, and 1,000 ppm resulted in average daily doses of approximately 1, 3, 9, 25, and 65 mg o-chloropyridine/kg body weight to males and 1, 3, 9, 27, and 70 mg/kg to females. In the 1,000 ppm groups, thinness was noted in seven of 10 males and all females on day 8 and also in five of 10 males on day 64; thinness noted on day 8 was likely due to dehydration from reduction in water consumption. Thinness was diagnosed based on the degree of visibility of the vertebrae and pelvic bones.

Table 4 Survival, Body Weights, and Water Consumption of Rats in the Three-month Drinking Water Study of o-Chloropyridine^a^

Concentration (ppm) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%) | Water Consumption Week 1 | Water Consumption Week 14
Male
0 | 10/10 | 90 ± 2 | 320 ± 6 | 230 ± 5 | | 14.7 | 17.3
10 | 10/10 | 93 ± 2 | 326 ± 7 | 233 ± 6 | 100 | 15.5 | 17.7
30 | 10/10 | 92 ± 2 | 326 ± 8 | 234 ± 7 | 102 | 15.1 | 13.6
100 | 10/10 | 91 ± 2 | 326 ± 8 | 235 ± 9 | 102 | 15.4 | 18.1
300 | 10/10 | 91 ± 2 | 309 ± 7 | 218 ± 7 | 97 | 13.6 | 17.5
1,000 | 10/10 | 94 ± 3 | 268 ± 6** | 173 ± 4** | 84 | 6.5 | 15.1
Female
0 | 10/10 | 86 ± 2 | 195 ± 4 | 109 ± 3 | | 12.5 | 13.4
10 | 10/10 | 88 ± 2 | 200 ± 2 | 112 ± 3 | 103 | 13.8 | 17.7
30 | 10/10 | 87 ± 1 | 200 ± 4 | 113 ± 4 | 103 | 13.0 | 14.8
100 | 10/10 | 88 ± 2 | 196 ± 2 | 108 ± 3 | 101 | 12.6 | 17.4
300 | 10/10 | 86 ± 2 | 190 ± 3 | 104 ± 3 | 97 | 12.2 | 12.7
1,000 | 10/10 | 87 ± 2 | 174 ± 2** | 87 ± 3** | 89 | 6.1 | 15.8

** Significantly different (P ≤ 0.01) from the control group by Williams’ test.

^a^ Weights and weight changes are given as mean ± standard error. Water consumption is expressed as grams per animal per day.

^b^ Number of animals surviving at 14 weeks/number initially in group.

Figure 2

Growth Curves for Rats Exposed to o-Chloropyridine in Drinking Water for Three Months

On day 4, the hematology findings demonstrated a small (approximately 10%) increase in the circulating erythron (i.e., an erythrocytosis). The erythrocytosis was evidenced by increases in hematocrit values, hemoglobin concentrations, and erythrocyte counts of the 1,000 ppm males (Table 5 and Table B-1). Additionally, urea nitrogen concentrations increased in the 1,000 ppm males on day 4 (Table B-1). These early changes may be the result of dehydration; there was an approximate 50% reduction in water intake during week 1 of the study (Table 4). The increases in the erythron and serum urea nitrogen were transient and disappeared by day 22, being replaced by an apparent dose-related erythron decrease in male and female rats exposed to 100 ppm or greater. The erythron decrease was small (≤10%) and was demonstrated by decreased hematocrit values and hemoglobin concentrations. The erythrocyte counts were unaffected in this case; however, there were small reductions (≤5%) in erythrocyte size (microcytosis), evidenced by decreases in the mean cell volume. By week 14, the erythron decrease had progressed to include decreases in the erythrocyte count and increases in reticulocyte count in the 300 ppm male and 1,000 ppm male and female rats. While the magnitude of these changes were small, they were supported by histologic changes in the bone marrow and spleen.

Table 5 Selected Clinical Pathology Data for Rats in the Three-month Drinking Water Study of o-Chloropyridine^a^

| 0 ppm | 10 ppm | 30 ppm | 100 ppm | 300 ppm | 1,000 ppm
Male
Hematology
n
Day 4 | 10 | 10 | 10 | 9 | 9 | 10
Day 22 | 10 | 10 | 10 | 10 | 10 | 10
Week 14 | 9 | 10 | 10 | 10 | 10 | 10
Hematocrit (%)
Day 4 | 40.0 ± 0.4 | 39.8 ± 0.4 | 40.5 ± 0.6 | 38.8 ± 0.5 | 39.6 ± 0.5 | 43.3 ± 0.9*
Day 22 | 43.4 ± 0.4 | 42.7 ± 0.4 | 42.6 ± 0.4 | 41.2 ± 0.6** | 41.5 ± 0.5** | 39.6 ± 0.4**
Week 14 | 45.5 ± 0.6 | 45.2 ± 0.3 | 46.3 ± 0.3 | 44.5 ± 0.9 | 42.9 ± 0.4** | 41.7 ± 0.4**
Hemoglobin (g/dL)
Day 4 | 13.4 ± 0.1 | 13.4 ± 0.1 | 13.6 ± 0.2 | 13.1 ± 0.2 | 13.3 ± 0.2 | 14.5 ± 0.3*
Day 22 | 14.8 ± 0.1 | 14.5 ± 0.1 | 14.5 ± 0.1 | 14.1 ± 0.2** | 14.1 ± 0.2** | 13.5 ± 0.1**
Week 14 | 15.2 ± 0.2 | 15.1 ± 0.1 | 15.4 ± 0.1 | 15.0 ± 0.3 | 14.4 ± 0.1** | 13.9 ± 0.1**
Erythrocytes (10^6^/μL)
Day 4 | 6.80 ± 0.08 | 6.85 ± 0.10 | 6.92 ± 0.10 | 6.72 ± 0.09 | 6.95 ± 0.10 | 7.53 ± 0.14**
Day 22 | 7.50 ± 0.07 | 7.35 ± 0.09 | 7.37 ± 0.08 | 7.18 ± 0.11* | 7.30 ± 0.08 | 7.25 ± 0.08
Week 14 | 8.91 ± 0.11 | 8.75 ± 0.07 | 9.04 ± 0.08 | 8.76 ± 0.15 | 8.51 ± 0.06** | 8.42 ± 0.09**
Reticulocytes (10^6^/μL)
Day 4 | 0.46 ± 0.04 | 0.45 ± 0.04 | 0.54 ± 0.02 | 0.50 ± 0.05 | 0.46 ± 0.03 | 0.39 ± 0.02
Day 22 | 0.33 ± 0.04 | 0.33 ± 0.02 | 0.28 ± 0.02 | 0.30 ± 0.02 | 0.36 ± 0.04 | 0.41 ± 0.02
Week 14 | 0.26 ± 0.01 | 0.27 ± 0.02 | 0.27 ± 0.02 | 0.25 ± 0.02 | 0.37 ± 0.02** | 0.32 ± 0.03*
Mean cell volume (fL)
Day 4 | 58.8 ± 0.3 | 58.1 ± 0.2 | 58.5 ± 0.3 | 57.8 ± 0.3* | 56.9 ± 0.2** | 57.5 ± 0.2**
Day 22 | 57.9 ± 0.3 | 58.0 ± 0.3 | 57.7 ± 0.2 | 57.3 ± 0.3 | 56.8 ± 0.3** | 54.7 ± 0.2**
Week 14 | 51.2 ± 0.2 | 51.6 ± 0.2 | 51.3 ± 0.2 | 50.8 ± 0.3 | 50.5 ± 0.2* | 49.3 ± 0.3**
Mean cell hemoglobin (pg)
Day 4 | 19.7 ± 0.1 | 19.5 ± 0.1 | 19.6 ± 0.1 | 19.5 ± 0.1 | 19.1 ± 0.1** | 19.3 ± 0.1**
Day 22 | 19.8 ± 0.1 | 19.8 ± 0.1 | 19.7 ± 0.1 | 19.6 ± 0.1 | 19.4 ± 0.0** | 18.7 ± 0.1**
Week 14 | 17.0 ± 0.0 | 17.2 ± 0.1 | 17.1 ± 0.1 | 17.1 ± 0.1 | 16.9 ± 0.1 | 16.5 ± 0.1**
Mean cell hemoglobin concentration (g/dL)
Day 4 | 33.6 ± 0.1 | 33.6 ± 0.1 | 33.5 ± 0.1 | 33.7 ± 0.1 | 33.6 ± 0.1 | 33.5 ± 0.1
Day 22 | 34.1 ± 0.1 | 34.1 ± 0.1 | 34.0 ± 0.1 | 34.2 ± 0.1 | 34.1 ± 0.1 | 34.1 ± 0.1
Week 14 | 33.3 ± 0.1 | 33.3 ± 0.1 | 33.3 ± 0.1 | 33.6 ± 0.1 | 33.5 ± 0.1 | 33.4 ± 0.1
Clinical Chemistry
n | 10 | 10 | 10 | 10 | 10 | 10
Total protein (g/dL)
Day 4 | 5.7 ± 0.1 | 5.7 ± 0.0 | 5.8 ± 0.1 | 5.8 ± 0.1 | 5.9 ± 0.1 | 5.9 ± 0.1
Day 22 | 6.4 ± 0.0 | 6.4 ± 0.1 | 6.5 ± 0.1 | 6.5 ± 0.1 | 6.8 ± 0.1* | 6.6 ± 0.1
Week 14 | 7.3 ± 0.1 | 7.3 ± 0.1 | 7.5 ± 0.1 | 7.8 ± 0.1** | 8.0 ± 0.1** | 8.3 ± 0.1**
Albumin (g/dL)
Day 4 | 4.1 ± 0.0 | 4.1 ± 0.0 | 4.1 ± 0.0 | 4.1 ± 0.0 | 4.2 ± 0.0 | 4.3 ± 0.1*
Day 22 | 4.4 ± 0.0 | 4.4 ± 0.1 | 4.5 ± 0.1 | 4.6 ± 0.0** | 4.7 ± 0.1** | 4.7 ± 0.1**
Week 14 | 4.9 ± 0.0 | 4.9 ± 0.0 | 5.0 ± 0.0* | 5.2 ± 0.1** | 5.4 ± 0.1** | 5.7 ± 0.0**
Bile acids (µmol/L)
Day 4 | 3.8 ± 1.4 | 26.5 ± 2.1 | 26.4 ± 1.3 | 33.8 ± 2.2** | 49.8 ± 6.4** | 41.0 ± 5.4**
Day 22 | 25.7 ± 1.1 | 25.5 ± 1.2 | 31.0 ± 2.6 | 28.0 ± 2.0 | 34.9 ± 2.9** | 39.1 ± 2.8**
Week 14 | 31.1 ± 3.4 | 26.0 ± 1.0 | 29.0 ± 1.9 | 26.1 ± 0.8 | 33.1 ± 3.1 | 39.2 ± 2.9
Female
n
Day 4 | 10 | 9 | 10 | 10 | 10 | 9
Day 22 | 10 | 10 | 10 | 10 | 10 | 10
Week 14 | 10 | 10 | 10 | 10 | 10 | 10
Hematocrit (%)
Day 4 | 42.6 ± 0.5 | 41.4 ± 0.5 | 42.6 ± 0.4 | 40.6 ± 1.1 | 39.8 ± 0.8* | 44.9 ± 0.8
Day 22 | 44.9 ± 0.3 | 45.9 ± 0.4 | 44.4 ± 0.4 | 43.5 ± 0.3* | 42.4 ± 0.6** | 42.4 ± 1.1**
Week 14 | 44.3 ± 0.8 | 45.2 ± 0.3 | 45.1 ± 0.3 | 43.7 ± 0.7 | 42.6 ± 0.2** | 40.7 ± 0.4**
Hemoglobin (g/dL)
Day 4 | 14.4 ± 0.2 | 14.1 ± 0.2 | 14.4 ± 0.2 | 13.8 ± 0.4 | 13.6 ± 0.3 | 15.3 ± 0.3
Day 22 | 15.5 ± 0.1 | 15.9 ± 0.1 | 15.4 ± 0.1 | 15.2 ± 0.1 | 14.8 ± 0.2* | 14.7 ± 0.4**
Week 14 | 15.1 ± 0.2 | 15.4 ± 0.1 | 15.4 ± 0.1 | 15.0 ± 0.2 | 14.7 ± 0.1* | 13.9 ± 0.2**
Erythrocytes (10^6^/μL)
Day 4 | 7.33 ± 0.09 | 7.16 ± 0.09 | 7.35 ± 0.07 | 7.02 ± 0.19 | 6.93 ± 0.15 | 7.87 ± 0.13
Day 22 | 7.80 ± 0.07 | 7.95 ± 0.08 | 7.75 ± 0.08 | 7.70 ± 0.06 | 7.51 ± 0.13 | 7.74 ± 0.17
Week 14 | 8.30 ± 0.13 | 8.50 ± 0.05 | 8.48 ± 0.07 | 8.27 ± 0.12 | 8.17 ± 0.03 | 7.90 ± 0.07**
Reticulocytes (10^6^/μL)
Day 4 | 0.36 ± 0.01 | 0.35 ± 0.03 | 0.35 ± 0.01 | 0.36 ± 0.02 | 0.32 ± 0.02 | 0.28 ± 0.01**
Day 22 | 0.20 ± 0.01 | 0.20 ± 0.01 | 0.20 ± 0.01 | 0.19 ± 0.01 | 0.22 ± 0.03 | 0.29 ± 0.02*
Week 14 | 0.23 ± 0.02 | 0.26 ± 0.02 | 0.21 ± 0.02 | 0.23 ± 0.02 | 0.26 ± 0.03 | 0.33 ± 0.02**
Mean cell volume (fL)
Day 4 | 58.0 ± 0.2 | 57.8 ± 0.2 | 57.8 ± 0.3 | 57.8 ± 0.3 | 57.6 ± 0.2 | 57.1 ± 0.2**
Day 22 | 57.5 ± 0.2 | 57.7 ± 0.2 | 57.4 ± 0.3 | 56.6 ± 0.2* | 56.6 ± 0.4* | 54.6 ± 0.2**
Week 14 | 53.5 ± 0.2 | 53.2 ± 0.1 | 53.2 ± 0.1 | 52.8 ± 0.1** | 52.1 ± 0.2** | 51.5 ± 0.2**
Mean cell hemoglobin (pg)
Day 4 | 19.7 ± 0.1 | 19.7 ± 0.1 | 19.6 ± 0.1 | 19.7 ± 0.1 | 19.7 ± 0.1 | 19.4 ± 0.1
Day 22 | 19.9 ± 0.1 | 20.0 ± 0.1 | 19.9 ± 0.1 | 19.8 ± 0.1 | 19.7 ± 0.1 | 19.0 ± 0.1**
Week 14 | 18.2 ± 0.1 | 18.1 ± 0.1 | 18.1 ± 0.1 | 18.1 ± 0.1 | 18.0 ± 0.1 | 17.6 ± 0.1**
Mean cell hemoglobin concentration (g/dL)
Day 4 | 33.8 ± 0.1 | 34.0 ± 0.1 | 33.8 ± 0.1 | 34.1 ± 0.1 | 34.3 ± 0.1* | 34.0 ± 0.1
Day 22 | 34.5 ± 0.1 | 34.6 ± 0.1 | 34.7 ± 0.1 | 35.0 ± 0.1* | 34.8 ± 0.1 | 34.7 ± 0.1
Week 14 | 34.1 ± 0.2 | 34.1 ± 0.1 | 34.1 ± 0.1 | 34.4 ± 0.1 | 34.5 ± 0.2 | 34.0 ± 0.1
Clinical Chemistry
n | 10 | 10 | 10 | 10 | 10 | 10
Total protein (g/dL)
Day 4 | 5.9 ± 0.1 | 5.8 ± 0.0 | 6.0 ± 0.1 | 5.9 ± 0.0 | 5.9 ± 0.1 | 5.8 ± 0.1
Day 22 | 6.3 ± 0.1 | 6.6 ± 0.1 | 6.5 ± 0.2 | 6.5 ± 0.1 | 6.5 ± 0.1 | 6.6 ± 0.1
Week 14 | 6.9 ± 0.1 | 7.2 ± 0.1 | 7.5 ± 0.1** | 7.4 ± 0.1** | 7.5 ± 0.1** | 7.8 ± 0.1**
Albumin (g/dL)
Day 4 | 4.3 ± 0.0 | 4.3 ± 0.0 | 4.5 ± 0.0* | 4.3 ± 0.0 | 4.3 ± 0.0 | 4.4 ± 0.1
Day 22 | 4.6 ± 0.1 | 4.7 ± 0.0 | 4.7 ± 0.1 | 4.8 ± 0.1** | 4.8 ± 0.1* | 4.9 ± 0.1**
Week 14 | 5.1 ± 0.2 | 5.1 ± 0.1 | 5.3 ± 0.1* | 5.4 ± 0.1** | 5.4 ± 0.1** | 5.7 ± 0.1**
Bile acids (µmol/L)
Day 4 | 26.4 ± 1.3 | 24.6 ± 0.8 | 27.3 ± 2.2 | 26.9 ± 1.6 | 40.3 ± 3.8** | 31.7 ± 2.8*
Day 22 | 24.0 ± 0.8 | 30.1 ± 1.5* | 27.0 ± 1.4 | 23.1 ± 1.1 | 29.1 ± 1.7 | 27.2 ± 1.0
Week 14 | 27.0 ± 1.7 | 34.3 ± 2.9 | 32.6 ± 1.4 | 34.8 ± 3.3 | 30.8 ± 1.5 | 36.4 ± 3.2*

* Significantly different (P ≤ 0.05) from the control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.

An exposure concentration-related hyperalbuminemia, demonstrated by increased serum albumin concentrations, occurred in the 30 ppm or greater males and females at week 14; the 1,000 ppm groups demonstrated a 10% to 15% increase (Table 5 and Table B-1). The hyperalbuminemia was progressive and, on day 4, involved a minimal 5% increase in the 1,000 ppm males only. By day 22, the 100, 300, and 1,000 ppm males and females were affected. At week 14, the increased serum albumin was accompanied by proportional increases in the serum total protein concentration. There was also evidence of a potential alteration in hepatic function demonstrated by increased serum bile acid concentrations. The most consistent change occurred on day 4, involving the 300 and 1,000 ppm males and females. Though the mechanism was unknown, the effect leading to the bile acid increase was transient in males, and bile acid concentrations demonstrated amelioration by day 22 and were essentially resolved at week 14. Bile acid concentrations remained higher in female mice at week 14 compared to controls.

The absolute and relative (except 100 ppm) right kidney weights of all exposed groups of males and of female groups exposed to 30 ppm or greater were significantly greater than those of the control groups (Table 6 and Table C-2). Absolute and relative liver weights of males exposed to 100 ppm or greater and females exposed to 30 ppm or greater were significantly greater than those of the controls.

Table 6 Selected Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the Three-month Drinking Water Study of o-Chloropyridine^a^

| 0 ppm | 10 ppm | 30 ppm | 100 ppm | 300 ppm | 1,000 ppm
n | 1 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 320 ± 6 | 326 ± 7 | 326 ± 8 | 326 ± 8 | 309 ± 7 | 268 ± 6**
R. Kidney
Absolute | 0.95 ± 0.01 | 1.02 ± 0.02* | 1.04 ± 0.03* | 1.01 ± 0.02* | 1.02 ± 0.03* | 1.07 ± 0.02**
Relative | 2.978 ± 0.065 | 3.144 ± 0.036* | 3.172 ± 0.052* | 3.110 ± 0.081 | 3.304 ± 0.030** | 4.012 ± 0.052**
Liver
Absolute | 10.91 ± 0.29 | 11.76 ± 0.29 | 10.87 ± 0.78 | 13.17 ± 0.35** | 13.51 ± 0.40** | 14.33 ± 0.36**
Relative | 34.101 ± 0.737 | 36.114 ± 0.615 | 33.092 ± 1.788 | 40.530 ± 1.053** | 43.672 ± 0.620** | 53.553 ± 0.653**
Female
Necropsy body wt | 195 ± 4 | 200 ± 2 | 200 ± 4 | 196 ± 2 | 190 ± 3 | 174 ± 2**
R. Kidney
Absolute | 0.65 ± 0.02 | 0.67 ± 0.01 | 0.70 ± 0.01* | 0.69 ± 0.02* | 0.71 ± 0.01** | 0.74 ± 0.01**
Relative | 3.317 ± 0.047 | 3.347 ± 0.032 | 3.472 ± 0.050* | 3.530 ± 0.051** | 3.714 ± 0.058** | 4.259 ± 0.040**
Liver
Absolute | 5.80 ± 0.22 | 6.14 ± 0.14 | 6.77 ± 0.17** | 6.89 ± 0.12** | 7.94 ± 0.34** | 9.06 ± 0.21**
Relative | 29.632 ± 0.735 | 30.698 ± 0.619 | 33.784 ± 0.410** | 35.152 ± 0.373** | 41.684 ± 1.375** | 52.086 ± 0.597**

* Significantly different (P ≤ 0.05) from the control group by Williams’ test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Epididymal sperm counts (total and sperm/mg cauda) were significantly lower in males exposed to 1,000 ppm (Table 7 and Table D-1). There were no test article-related changes in the estrous cyclicity of rats exposed to o-chloropyridine (Table D-2, Table D-3, and Figure D-1).

Table 7 Summary of Reproductive Tissue Evaluations for Male Rats in the Three-month Drinking Water Study of o-Chloropyridine^a^

| 0 ppm | 100 ppm | 300 ppm | 1,000 ppm
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 320 ± 6 | 326 ± 8 | 309 ± 7 | 268 ± 6**
L. Cauda epididymis | 0.1510 ± 0.0067 | 0.1563 ± 0.0040 | 0.1548 ± 0.0041 | 0.1503 ± 0.0037
L. Epididymis | 0.4239 ± 0.0177 | 0.4579 ± 0.0097 | 0.4457 ± 0.0063 | 0.4222 ± 0.0079
L. Testis | 1.4547 ± 0.0387 | 1.5359 ± 0.0227 | 1.4795 ± 0.0269 | 1.4671 ± 0.0212
Spermatid measurements
Spermatid heads (10^6^/testis) | 169.75 ± 7.20 | 182.13 ± 5.88 | 170.88 ± 4.14 | 166.75 ± 4.25
Spermatid heads (10^6^/g testis) | 129.7 ± 3.6 | 131.9 ± 4.6 | 126.8 ± 2.8 | 125.6 ± 3.0
Epididymal spermatozoal measurements
Sperm motility (%) | 77.6 ± 1.0 | 71.7 ± 8.0 | 76.9 ± 1.4 | 77.4 ± 1.0
Sperm (10^6^/cauda epididymis) | 60.00 ± 4.43 | 68.75 ± 6.84 | 62.15 ± 5.53 | 42.40 ± 2.02*
Sperm (10^6^/g cauda epididymis) | 402 ± 29 | 443 ± 46 | 400 ± 32 | 283 ± 13*

* Significantly different (P ≤ 0.05) from the control group by Shirley’s or Dunn’s test.

** Significantly different (P ≤ 0.01) from the control group by Williams’ test.

^a^ Data are presented as mean ± standard error. Differences from the control group are not significant by Dunnett’s test (tissue weights) or Dunn’s test (spermatid measurements and sperm motility).

Incidences of clear cell focus in the liver were significantly increased in male rats exposed to 1,000 ppm; a slight increase was also observed in females at 1,000 ppm (Table 8, Table A-1, and Table A-2). The incidences of hepatocyte cytoplasmic vacuolization were significantly increased in 300 and 1,000 ppm males and in 1,000 ppm females; the severity of this lesion was increased in 1,000 ppm males.

Table 8 Incidences of Selected Nonneoplastic Lesions in Rats in the Three-month Drinking Water Study of o-Chloropyridine

| 0 ppm | 10 ppm | 30 ppm | 100 ppm | 300 ppm | 1,000 ppm
Male
Liver^a^ | 10 | 10 | 10 | 10 | 10 | 10
Clear Cell Focus^b^ | 0 | 0 | 0 | 0 | 0 | 6**
Hepatocyte, Vacuolization Cytoplasmic | 0 | 0 | 0 | 0 | 6** (1.0)^c^ | 9** (1.8)
Spleen | 10 | 10 | 10 | 10 | 10 | 10
Hematopoietic Cell Proliferation | 4 (1.8) | 8 (2.0) | 6 (1.8) | 6 (1.7) | 10** (2.0) | 10** (2.0)
Congestion | 4 (1.0) | 1 (1.0) | 2 (1.0) | 0* | 7 (1.0) | 10** (1.0)
Pigmentation | 10 (1.0) | 10 (1.0) | 10 (1.3) | 10 (1.0) | 10 (2.0) | 10 (2.0)
Bone Marrow | 10 | 10 | 10 | 10 | 10 | 10
Hyperplasia | 1 (1.0) | 0 | 2 (1.0) | 1 (1.0) | 9** (1.0) | 10** (1.9)
Kidney | 10 | 10 | 10 | 10 | 10 | 10
Renal Tubule, Accumulation, Hyaline Droplet | 10 (2.1) | 10 (2.4) | 10 (2.3) | 9 (1.8) | 5* (1.2) | 0**
Female
Liver | 10 | 10 | 10 | 10 | 10 | 10
Clear Cell Focus | 0 | 0 | 0 | 0 | 0 | 2
Hepatocyte, Vacuolization Cytoplasmic | 0 | 0 | 0 | 0 | 0 | 9** (1.3)
Spleen | 10 | 10 | 10 | 10 | 10 | 10
Hematopoietic Cell Proliferation | 3 (2.0) | 3 (1.3) | 6 (1.5) | 3 (1.7) | 7 (1.7) | 10** (1.9)
Congestion | 1 (2.0) | 7** (1.3) | 5 (1.6) | 6* (1.3) | 6* (1.0) | 10** (1.8)
Pigmentation | 10 (2.0) | 10 (2.2) | 10 (2.3) | 10 (2.4) | 10 (2.2) | 10 (3.0)
Bone Marrow | 10 | 10 | 10 | 10 | 10 | 10
Hyperplasia | 0 | 0 | 0 | 0 | 3 (1.0) | 9** (1.1)

* Significantly different (P ≤ 0.05) from the control group by the Fisher exact test.

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Clear cell foci were scattered throughout the section and were characterized by enlarged hepatocytes with clear cytoplasm, particularly in the perinuclear region, but often involving the entire cell. The increased size of the hepatocytes occasionally resulted in minimal compression at the margin of the lesion. Hepatocyte cytoplasmic vacuolization was characterized by individual or clusters of large hepatocytes with pale cytoplasm and indistinct or microvesicular cytoplasmic vacuoles scattered throughout the section.

Incidences of hematopoietic cell proliferation in the spleen were significantly increased in 300 and 1,000 ppm males and in 1,000 ppm females (Table 8, Table A-1, and Table A-2). Incidences of splenic congestion were significantly increased in 1,000 ppm males and in most exposed groups of females. Pigmentation occurred in the spleen of every rat in the study, but the severity of the lesion was increased in 300 and 1,000 ppm males and all exposed groups of females.

Splenic hematopoietic cell proliferation was characterized by an increase of primarily erythroid precursors in the sinusoids of the spleen above background levels. Severity grades were evaluated semiquantitatively and ranged from a minimal to mild increase in cellularity. Background hematopoietic cell presence in control animals was fairly minimal although all animals had at least some hematopoietic precursors in the spleen characterized by scattered individual and small clusters of hematopoietic cells throughout the red pulp. The control males had a slightly higher background level of hematopoietic cells than the control females and therefore the severity grade of hematopoietic cell proliferation was judged relative to the appropriate sex-matched control. Minimal hematopoietic proliferation consisted of 10% to 20% increased numbers of small clusters of hematopoietic cells in the red pulp compared to the majority of the controls. Mild hematopoietic cell proliferation was characterized by an approximately 21% to 50% increase in numbers of small clusters throughout the red pulp, but without confluence of clusters of hematopoietic cells. As stated above, background hematopoiesis in controls was not particularly prominent and therefore a minimal to mild increase in hematopoietic cells still did not result in loss of architecture or impingement on the white pulp elements.

Splenic congestion was characterized by an increased amount of blood in the red pulp of the spleen compared to controls. Severity of congestion was assessed semiquantitatively by the numbers (density) of red cells in the red pulp and varied from minimal to mild. As the numbers of red cells increased, less space was noted around individual red blood cells and the overall color of the spleen became more brightly eosinophilic. Minimal congestion had approximately 10% to 20% more red blood cells than controls and was best appreciated in the subcapsular red pulp. Mild congestion had 21% to 35% more red cells in sinusoids than controls, particularly in the subcapsular areas at the lateral edges of the spleen as seen on cross section, and also in red pulp in the central areas of the spleen. However, with both minimal and mild congestion, the overall architecture of the spleen was retained.

Pigmentation in the spleen was characterized by an increase in gold-colored pigment within macrophages. It is suspected that this pigmentation represents hemosiderin. Severity of pigmentation was assessed semiquantitatively and a threshold was not utilized. All spleens had at least some pigmentation with increasing severity in both the number of macrophages that contained pigment and in the amount of pigment within the macrophages. Minimal pigmentation was characterized by a faint gold pigment in 20% to 40% of individual macrophages scattered throughout the red pulp. Mild pigmentation was characterized by an approximately 50% increase in the amount of pigment in individual macrophages so that the cytoplasm was a more intense gold color. Also, mild pigmentation was characterized by an increased number of pigment-containing macrophages with at least 50% of macrophages containing pigment; occasional clusters of macrophages with distended cytoplasm containing pigment were noted. Moderate pigmentation had increased numbers of macrophages containing pigment and greater than 80% of macrophages had at least some pigmented material in the cytoplasm. Clusters of macrophages, containing abundant pigment distending the cytoplasm, were more numerous in spleens with moderate pigmentation than in spleens with mild pigmentation.

The incidences of bone marrow hyperplasia were significantly increased in 300 and 1,000 ppm males and 1,000 ppm females (Table 8, Table A-1, and Table A-2). Bone marrow hyperplasia was evaluated for overall cellularity of hematopoietic cells (myeloid, erythroid, and megakaryocytic cell lines). The cellularity was assessed semiquantitatively as a percentage of hematopoietic cells to fat in the marrow of the femur. In control males, the bone marrow was approximately 20% hematopoietic cells and 80% fat. In males, minimal hyperplasia was characterized by 21% to 40% hematopoietic cells and mild hyperplasia was diagnosed when 41% to 60% of the marrow was composed of hematopoietic cells. Control females had a higher percentage of fat in the marrow than male controls with approximately 10% hematopoietic cells and 90% fat. Minimal hyperplasia was characterized by approximately 11% to 20% hematopoietic cells and 80% fat. Mild hyperplasia was diagnosed when the marrow contained approximately 21% to 50% hematopoietic cells. Bone marrow hyperplasia was characterized by an increase in erythroid and myeloid cell lines with all maturation stages represented. Numbers of megakaryocytes also increased with increasing bone marrow cellularity, and mast cells tended to increase with increasing cellularity. The myeloid/erythroid ratio was maintained between 1:1 and 2.5:1 across all groups, although there was a slight relative increase in the erythroid cells.

Significant decreases in the incidences of renal tubule hyaline droplet accumulation in the kidney occurred in 300 and 1,000 ppm males (Table 8 and Table A-1). Hyaline droplets are normal lysosomal accumulations of α2u-globulin, a protein specific to male rats, from the glomerular filtrate. This eosinophilic accumulation normally occurs within the cytoplasm of proximal convoluted tubules in the renal cortex.

## Mice

### Two-week Dermal Study

All mice survived to the end of the study (Table 9). The final mean body weights and body weight gains of all dosed groups were similar to those of the vehicle control groups. There were no clinical findings related to o-chloropyridine administration.

Table 9 Survival and Body Weights of Mice in the Two-week Dermal Study of o-Chloropyridine^a^

Dose (mg/kg) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 5/5 | 23.7 ± 0.3 | 25.7 ± 0.3 | 2.0 ± 0.3
6.25 | 5/5 | 23.3 ± 0.7 | 26.4 ± 0.5 | 3.1 ± 0.4 | 103
12.5 | 5/5 | 23.5 ± 0.6 | 26.8 ± 0.4 | 3.3 ± 0.6 | 104
25 | 5/5 | 23.6 ± 0.7 | 26.1 ± 0.5 | 2.5 ± 0.4 | 102
50 | 5/5 | 23.5 ± 0.5 | 25.7 ± 0.3 | 2.2 ± 0.2 | 100
100 | 5/5 | 23.1 ± 0.9 | 25.6 ± 0.7 | 2.5 ± 0.3 | 100
Female
0 | 5/5 | 19.9 ± 0.7 | 23.2 ± 0.6 | 3.3 ± 0.2
6.25 | 5/5 | 19.5 ± 0.6 | 23.1 ± 0.4 | 3.6 ± 0.3 | 100
12.5 | 5/5 | 19.8 ± 0.6 | 22.8 ± 0.6 | 3.0 ± 0.3 | 98
25 | 5/5 | 19.8 ± 0.6 | 23.0 ± 0.6 | 3.2 ± 0.2 | 99
50 | 5/5 | 19.9 ± 0.7 | 22.7 ± 0.6 | 2.8 ± 0.4 | 98
100 | 5/5 | 20.0 ± 0.4 | 23.3 ± 0.4 | 3.3 ± 0.2 | 100

^a^ Weights and weight changes are given as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test.

^b^ Number of animals surviving at 17 days/number initially in group.

Relative right kidney weights of 50 and 100 mg/kg males and 25 mg/kg females were significantly greater than those of the vehicle controls (Table 10 and Table C-3). No gross or microscopic lesions were considered related to o-chloropyridine administration.

Table 10 Kidney Weights and Kidney-Weight-to-Body-Weight Ratios for Mice in the Two-week Dermal Study of o-Chloropyridine^a^

| Vehicle Control | 6.25 mg/kg | 12.5 mg/kg | 25 mg/kg | 50 mg/kg | 100 mg/kg
n | 5 | 5 | 5 | 5 | 5 | 5
Male
Necropsy body wt | 25.7 ± 0.3 | 26.4 ± 0.5 | 26.8 ± 0.4 | 26.1 ± 0.5 | 25.7 ± 0.3 | 25.6 ± 0.7
R. Kidney
Absolute | 0.26 ± 0.00 | 0.27 ± 0.01 | 0.28 ± 0.00 | 0.28 ± 0.01 | 0.28 ± 0.01 | 0.28 ± 0.01
Relative | 10.059 ± 0.254 | 10.379 ± 0.134 | 10.608 ± 0.230 | 10.544 ± 0.316 | 10.940 ± 0.277* | 10.921 ± 0.248*
Female
Necropsy body wt | 23.2 ± 0.6 | 23.1 ± 0.4 | 22.8 ± 0.6 | 23.0 ± 0.6 | 22.7 ± 0.6 | 23.3 ± 0.4
R. Kidney
Absolute | 0.20 ± 0.01 | 0.20 ± 0.01 | 0.20 ± 0.00 | 0.21 ± 0.01 | 0.20 ± 0.01 | 0.21 ± 0.01
Relative | 8.383 ± 0.185 | 8.835 ± 0.119 | 8.598 ± 0.185 | 9.074 ± 0.133* | 8.613 ± 0.194 | 8.849 ± 0.172

* Significantly different (P ≤ 0.05) from the vehicle control group by Williams’ or Dunnett’s test.

^a^ Kidney weights (absolute weights) and body weights are given in grams; kidney-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Exposure concentration selection rationale: Exposure concentrations for the 3-month drinking water study were selected for comparison to the 3-month pyridine study results.^33^

### Three-month Drinking Water Study

There were no treatment-related deaths in either sex (one control female was found dead) (Table 11). The final mean body weight and body weight gain of 1,000 ppm males were significantly less than those of the control group; the mean body weight gain of 300 ppm females was significantly greater than that of the controls (Table 11 and Figure 3). Water consumption by the 1,000 ppm groups was less than that of the control groups during the first week of the study. Drinking water concentrations of 10, 30, 100, 300, and 1,000 ppm resulted in average daily doses of approximately 1.5, 4.5, 15, 41, and 110 mg o-chloropyridine/kg body weight to males and 1.3, 4, 12, 38, and 92 mg/kg to females. There were no clinical findings related to o-chloropyridine exposure.

Table 11 Survival, Body Weights, and Water Consumption of Mice in the Three-month Drinking Water Study of o-Chloropyridine^a^

Concentration (ppm) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%) | Water Consumption Week 1 | Water Consumption Week 14
Male
0 | 10/10 | 23.2 ± 0.3 | 40.8 ± 0.9 | 17.6 ± 0.8 | | 4.8 | 4.5
10 | 10/10 | 23.2 ± 0.4 | 42.4 ± 1.1 | 19.1 ± 1.2 | 104 | 5.1 | 4.6
30 | 10/10 | 23.3 ± 0.4 | 42.4 ± 0.6 | 19.2 ± 0.6 | 104 | 5.4 | 4.9
100 | 10/10 | 23.3 ± 0.3 | 40.2 ± 1.2 | 16.8 ± 1.0 | 99 | 5.3 | 5.4
300 | 10/10 | 23.1 ± 0.3 | 40.5 ± 1.2 | 17.4 ± 1.1 | 99 | 4.4 | 4.7
1,000 | 10/10 | 23.1 ± 0.2 | 33.0 ± 0.5** | 9.8 ± 0.6** | 81 | 3.2 | 3.3
Female
0 | 9/10^c^ | 18.6 ± 0.4 | 28.5 ± 1.4 | 9.7 ± 1.2 | | 2.8 | 3.5
10 | 10/10 | 19.1 ± 0.3 | 31.8 ± 1.0 | 12.8 ± 1.0 | 112 | 3.0 | 3.3
30 | 10/10 | 18.8 ± 0.3 | 31.2 ± 1.3 | 12.4 ± 1.1 | 109 | 2.7 | 3.4
100 | 10/10 | 19.0 ± 0.3 | 30.3 ± 1.1 | 11.3 ± 0.9 | 106 | 2.3 | 3.4
300 | 10/10 | 18.1 ± 0.5 | 31.9 ± 0.8 | 13.8 ± 0.7* | 112 | 3.3 | 3.4
1,000 | 10/10 | 18.6 ± 0.4 | 28.4 ± 0.6 | 9.9 ± 0.5 | 100 | 1.6 | 2.8

* Significantly different (P ≤ 0.05) from the control group by Dunnett’s test.

** Significantly different (P ≤ 0.01) from the control group by Williams’ test.

^a^ Weights and weight changes are given as mean ± standard error. Water consumption is expressed as grams per animal per day.

^b^ Number of animals surviving at 14 weeks/number initially in group.

^c^ Week of death: 11.

Figure 3

Growth Curves for Mice Exposed to o-Chloropyridine in Drinking Water for Three Months

The hematology data for mice are presented in Table 12 and Table B-2. Similar to what occurred in the rat study, at week 14, a decreased erythron occurred; however, this was only observed in the 1,000 ppm females. The erythron decrease was small (<10%) and was demonstrated by decreases in hematocrit value, hemoglobin concentration and erythrocyte count. As with the rats, the erythron decrease was accompanied by a small reduction (approximately 3%) in erythrocyte size, evidenced by a decrease in the mean cell volume.

Table 12 Selected Hematology Data for Mice in the Three-month Drinking Water Study of o-Chloropyridine^a^

| 0 ppm | 10 ppm | 30 ppm | 100 ppm | 300 ppm | 1,000 ppm
Male
n | 10 | 10 | 10 | 10 | 10 | 10
Hematocrit (%) | 51.2 ± 0.4 | 51.4 ± 0.5 | 50.4 ± 0.7 | 50.2 ± 0.4 | 50.3 ± 0.6 | 50.5 ± 0.6
Hemoglobin (g/dL) | 16.4 ± 0.1 | 16.5 ± 0.1 | 16.1 ± 0.2 | 16.1 ± 0.1 | 16.2 ± 0.2 | 16.2 ± 0.2
Erythrocytes (10^6^/µL) | 10.63 ± 0.09 | 10.78 ± 0.10 | 10.46 ± 0.13 | 10.65 ± 0.07 | 10.67 ± 0.11 | 10.69 ± 0.08
Reticulocytes (10^6^/µL) | 0.25 ± 0.02 | 0.27 ± 0.02 | 0.29 ± 0.03 | 0.28 ± 0.02 | 0.28 ± 0.03 | 0.26 ± 0.03
Mean cell volume (fL) | 47.3 ± 0.3 | 47.3 ± 0.3 | 47.5 ± 0.2 | 46.8 ± 0.1 | 47.0 ± 0.4 | 46.7 ± 0.2
Mean cell hemoglobin (pg) | 15.2 ± 0.1 | 15.2 ± 0.1 | 15.2 ± 0.1 | 15.1 ± 0.1 | 15.1 ± 0.1 | 14.9 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 32.1 ± 0.2 | 32.1 ± 0.1 | 32.0 ± 0.1 | 32.2 ± 0.1 | 32.2 ± 0.1 | 32.1 ± 0.1
Female
n | 9 | 10 | 10 | 10 | 10 | 10
Hematocrit (%) | 50.9 ± 1.1 | 50.5 ± 0.7 | 48.9 ± 0.4 | 50.5 ± 0.4 | 48.8 ± 0.6 | 46.6 ± 0.4**
Hemoglobin (g/dL) | 16.2 ± 0.3 | 16.0 ± 0.2 | 15.7 ± 0.1 | 16.2 ± 0.1 | 15.7 ± 0.2 | 15.1 ± 0.1**
Erythrocytes (10^6^/µL) | 10.56 ± 0.20 | 10.42 ± 0.12 | 10.23 ± 0.09 | 10.54 ± 0.07 | 10.22 ± 0.13 | 9.96 ± 0.09**
Reticulocytes (10^6^/µL) | 0.40 ± 0.03 | 0.33 ± 0.03 | 0.32 ± 0.03 | 0.37 ± 0.03 | 0.37 ± 0.03 | 0.31 ± 0.03
Mean cell volume (fL) | 48.2 ± 0.2 | 48.2 ± 0.1 | 47.9 ± 0.2 | 47.9 ± 0.2 | 47.7 ± 0.2 | 46.9 ± 0.2**
Mean cell hemoglobin (pg) | 15.3 ± 0.1 | 15.3 ± 0.0 | 15.3 ± 0.1 | 15.4 ± 0.1 | 15.4 ± 0.0 | 15.2 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 31.8 ± 0.1 | 31.7 ± 0.1 | 32.0 ± 0.1 | 32.0 ± 0.1 | 32.2 ± 0.1 | 32.4 ± 0.1**

** Significantly different (P ≤ 0.01) from the control group by Shirley’s test.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.

The absolute and relative liver weights of all exposed groups of males and of 300 (absolute, 32.8%) and 1,000 ppm (absolute, 59%) females were significantly greater than those of the control groups (Table 13 and Table C-4). The absolute (15.8%) and relative right kidney weights of 1,000 ppm females were significantly greater than those of the controls. There were no significant differences in any of the reproductive organ weights or sperm parameters of males, or in the estrous cyclicity of females, at any exposure concentration tested when compared to the control groups (Table D-4, Table D-5, and Table D-6 and Figure D-2).

Table 13 Selected Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Three-month Drinking Water Study of o-Chloropyridine^a^

| 0 ppm | 10 ppm | 30 ppm | 100 ppm | 300 ppm | 1,000 ppm
Male
n | 10 | 10 | 10 | 10 | 10 | 10
Necropsy body wt | 40.8 ± 0.9 | 42.4 ± 1.1 | 42.4 ± 0.6 | 40.2 ± 1.2 | 40.5 ± 1.2 | 33.0 ± 0.5**
R. Kidney
Absolute | 0.34 ± 0.01 | 0.35 ± 0.01 | 0.35 ± 0.01 | 0.35 ± 0.01 | 0.35 ± 0.01 | 0.31 ± 0.01
Relative | 8.237 ± 0.218 | 8.203 ± 0.090 | 8.193 ± 0.244 | 8.631 ± 0.217 | 8.556 ± 0.229 | 9.242 ± 0.369*
Liver
Absolute | 1.70 ± 0.06 | 1.89 ± 0.07* | 1.95 ± 0.04* | 1.84 ± 0.07* | 2.01 ± 0.08** | 1.95 ± 0.05**
Relative | 41.624 ± 0.778 | 44.531 ± 0.718* | 45.851 ± 0.819** | 45.766 ± 0.974** | 49.467 ± 0.796** | 59.121 ± 0.830**
Female
n | 9 | 10 | 10 | 10 | 10 | 10
Necropsy body wt | 28.5 ± 1.4 | 31.8 ± 1.0 | 31.2 ± 1.3 | 30.3 ± 1.1 | 31.9 ± 0.8 | 28.4 ± 0.6
R. Kidney
Absolute | 0.19 ± 0.01 | 0.20 ± 0.00 | 0.19 ± 0.01 | 0.19 ± 0.01 | 0.20 ± 0.00 | 0.22 ± 0.01**
Relative | 6.866 ± 0.352 | 6.203 ± 0.206 | 6.212 ± 0.170 | 6.232 ± 0.174 | 6.321 ± 0.154 | 7.676 ± 0.156*
Liver
Absolute | 1.22 ± 0.09 | 1.37 ± 0.04 | 1.34 ± 0.05 | 1.35 ± 0.07 | 1.62 ± 0.05** | 1.94 ± 0.0.05**
Relative | 42.778 ± 1.560 | 43.065 ± 1.066 | 43.266 ± 0.645 | 44.466 ± 1.122 | 50.818 ± 1.290** | 68.154 ± 1.026**

* Significantly different (P ≤ 0.05) from the control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Incidences of hepatocyte centrilobular hypertrophy occurred with positive trends in exposed groups of males and females, and the incidences were significantly increased in the 300 and 1,000 ppm groups compared to those in the controls (Table 14, Table A-3, and Table A-4); the severity of this lesion also increased with exposure concentration. The lesion was characterized by minimal to mild enlargement (hypertrophy) of hepatocytes that were centrilobular in distribution. Hypertrophic hepatocytes had homogeneous or slightly granular eosinophilic cytoplasm. The nuclei were often enlarged and contained prominent basophilic chromatin aggregates.

Table 14 Incidences of Hepatocyte Centrilobular Hypertrophy in the Liver of Mice in the Three-month Drinking Water Study of o-Chloropyridine

| 0 ppm | 10 ppm | 30 ppm | 100 ppm | 300 ppm | 1,000 ppm
Male
Number Examined Microscopically | 10 | 10 | 10 | 10 | 10 | 10
Centrilobular, Hepatocyte, Hypertrophy^a^ | 0 | 0 | 0 | 1 (1.0)^b^ | 6** (1.5) | 9** (2.1)
Female
Number Examined Microscopically | 10 | 10 | 10 | 10 | 10 | 10
Centrilobular, Hepatocyte, Hypertrophy | 0 | 0 | 0 | 0 | 4* (1.0) | 10** (1.5)

* Significantly different (P ≤ 0.05) from the control group by the Fisher exact test.

** P ≤ 0.01.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = mild, 2 =minimal, 3 = moderate, 4 = marked.

## Absorption, Distribution, Metabolism, Excretion, and Toxicokinetics

The metabolism and disposition of o-chloropyridine was investigated following a single oral, intravenous, or intraperitoneal dose in male F344 rats (Appendix J). For all studies, formulations were prepared by addition of Alkamuls^®^ EL-620/L (no more than 15% of the dose) (Rhodia, Inc., Cranbury, NJ) to known amounts of o-chloropyridine following which distilled deionized water and the appropriate amount of [^14^C]-o-chloropyridine were added. Dosing volumes were either 5 mL/kg (oral gavage and intraperitoneal injection) or 1 mL/kg (intravenous injection). Oral doses were administered by intragastric gavage using a syringe equipped with a 16-gauge gavage needle. Intravenous doses were injected into a lateral tail vein using a syringe equipped with a 27-gauge needle.

Following gavage administration of 0.1 or 10 mg [^14^C]-o-chloropyridine/kg, there was no dose-related difference in the disposition. Approximately 82% of the administered dose was recovered by 72 hours following administration. The absorption was rapid with maximum blood concentration being reached within 30 minutes following administration. The distribution (t_1/2α_) and elimination (t_1/2β_) half-lives, estimated based on the measurement of the total radioactivity in blood were 1.14 hours and 46 hours, respectively. Excretion in urine accounted for approximately 36% to 39% and that in feces about 28%. The observation that 27% of a 50 mg/kg intraperitoneal dose was excreted in bile in rats by 4 hours after administration suggests that the high fecal excretion following gavage administration was likely due to biliary excretion and not due to poor absorption. Approximately 11% to 13% of the gavage dose was recovered as CO_2_ and approximately 1% was eliminated in breath as volatile organics. The total radioactivity in tissue at 72 hours following administration was approximately 3% to 4% with the highest tissue:blood ratios observed in the liver and kidney. Profiling of urine showed that the compound is readily metabolized. Three major metabolites carrying most of the radioactivity were found to contain disubstituted pyridine structures, one of which was identified as 2-chloro-5-hydroxypyridine.

Following intravenous administration of 1 mg/kg [^14^C]-o-chloropyridine in male F344/N rats, the distribution (T_1/2α_) and elimination (T_1/2β_) half-lives were 0.103 hours and 1.04 hours, respectively, based on the measurement of parent compound (Appendix J).

## Genetic Toxicology

o-Chloropyridine (10 to10,000 µg/plate) was mutagenic in Salmonella typhimurium strains TA98 and TA100 when tested with induced rat or hamster liver S9 metabolic activation enzymes; no mutagenic activity was observed in either strain in the absence of metabolic activation (Table E-1). In both TA98 and TA100, the mutagenic activity observed with o-chloropyridine was stronger with hamster S9 (higher magnitude response observed at lower concentrations of o-chloropyridine). In vivo, no increases in the frequencies of micronucleated normochromatic erythrocytes were observed in peripheral blood samples from male or female mice exposed to o-chloropyridine (10 to 1,000 ppm) in drinking water for 3 months (Table E-2). In addition, no significant exposure concentration-related changes in the percentage of immature (polychromatic) erythrocytes were observed, suggesting that exposure to o-chloropyridine did not alter the process of erythropoiesis in the bone marrow of mice.