# Materials and Methods

## Procurement and Characterization

### o-Chloropyridine

o-Chloropyridine was obtained from Aldrich Chemical Company (Milwaukee, WI) in one lot (15306CN) that was used in the 2-week dermal and 3-month drinking water studies. Identity and purity analyses were conducted by the analytical chemistry laboratory at Battelle (Columbus, OH, and Richland, WA), Chemir/Polytech Laboratories, Inc. (Maryland Heights, MO), Galbraith Laboratories, Inc. (Knoxville, TN), and the study laboratory, BioReliance Corporation (Rockville, MD) (Appendix F). Reports on analyses performed in support of the o-chloropyridine studies are on file at the National Institute of Environmental Health Sciences.

The chemical, a clear colorless liquid, was identified as o-chloropyridine by infrared (IR) and proton and carbon-13 nuclear magnetic resonance spectroscopy. The purity of lot 15306CN was determined by elemental analyses and two gas chromatography (GC) systems. Elemental analyses for carbon, hydrogen, nitrogen, and chlorine were in agreement with the theoretical values for o-chloropyridine. GC by both systems indicated one major peak and two impurities with areas at least 0.1% relative to the major peak area. The overall purity of lot 15306CN was determined to be 99% or greater.

To ensure stability, the bulk chemical was stored at room temperature in sealed amber glass bottles under a headspace of inert gas, protected from light and moisture. Periodic reanalyses of the bulk chemical were performed during the 2-week and 3-month studies using GC, and no degradation of the bulk chemical was detected.

### Ethanol

95% Ethanol was obtained from Clear Spring Distilling Company (Clearwater, KY) in one lot (21049312) that was used as the dosing vehicle in the 2-week dermal studies. Lot 21049312, a clear liquid, was identified as ethanol by IR spectroscopy. The purity of lot 21049312 was determined using GC. Analysis indicated one major peak and three impurities each with a relative concentration of less than or equal to 0.0001%.

## Preparation and Analysis of Dose Formulations

### Dermal Studies

The dose formulations were prepared by mixing o-chloropyridine with 95% ethanol (Table F-2). Stability studies of a 3.125 mg/mL dose formulation were performed by the analytical chemistry laboratory with GC. Stability was confirmed for at least 43 days for dose formulations stored in sealed amber glass vials at room temperature, 5°C, or −20°C. Data from a simulated animal room stability study indicated that o-chloropyridine is stable dissolved in 95% ethanol when exposed to light for up to 3 hours at room temperature. The dose formulations were stored under a headspace of inert gas in refrigerated amber glass vials with Teflon^®^-lined lids for up to 23 days.

The dose formulations were analyzed on the day they were prepared by the study laboratory using GC. All seven dose formulations analyzed for rats and mice were within 10% of the target concentrations. Animal room samples of these dose formulations were also analyzed; one of five formulations for rats and all five formulations for mice were within 10% of the target concentrations. High concentrations measured for some of the rat animal room samples were attributed to improper sealing of the vials after dosing and possible solvent evaporation.

### Drinking Water Studies

The dose formulations were prepared by mixing o-chloropyridine with tap water (Table F-2). Stability studies of the 10 ppm dose formulation were performed by the analytical chemistry laboratory with high-performance liquid chromatography (HPLC). Stability was confirmed for at least 43 days for dose formulations stored in sealed polyethylene bottles protected from light at 5°C and for at least 8 days under simulated animal room conditions. The dose formulations were stored refrigerated in Cubitainers^®^ with taps, protected from light, for up to 21 days.

The dose formulations were analyzed at the beginning, midpoint, and end of the studies by the study laboratory using HPLC; animal room samples of these dose formulations were also analyzed. All 15 dose formulations analyzed and used for rats and mice were within 10% of the target concentrations. Of the animal room samples analyzed, all 15 for rats and 12 of 15 for mice were within 10% of the target concentrations, and the remaining three were less than 12% of the target concentration.

## Animal Welfare

Animal care and use are in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by the Association for the Assessment and Accreditation of Laboratory Animal Care International. Studies were approved by the BioReliance Corporation Animal Care and Use Committee and conducted in accordance with all relevant NIH and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Two-week Dermal Studies

Male and female F344/N rats and B6C3F1/N mice were obtained from the NTP colony maintained at Taconic Farms, Inc. (Germantown, NY). On receipt, the rats and mice were 4 weeks old. Animals were quarantined for 12 (rats) or 13 (mice) days and were 5 to 6 weeks old on the first day of the studies. o-Chloropyridine in 95% ethanol was applied using automatic (adjustable volume) pipettes to the center of a shaved area of skin on the dorsal surface from just posterior to the scapulae to the base of the tail; the shaved area was larger than the application site. A constant concentration of test chemical per dose concentration was administered to each animal at volumes of 0.5 mL/kg body weight for rats and 2 mL/kg for mice. Five male and five female rats and mice per dose group were administered o-chloropyridine in ethanol 5 days per week over a 16-day period (12 dose days). Rats and mice were administered 0, 6.25, 12.5, 25, 50, or 100 mg o-chloropyridine/kg body weight. Vehicle control animals were administered ethanol alone. Feed and water were available ad libitum. Rats and mice were housed individually. Clinical findings were recorded daily. The animals were weighed initially, on day 8, and at the end of the studies. Prior to dosing and at the start of the studies, five male and five female rats and mice were selected for parasite evaluation and gross observation for disease presence. Details of the study design and animal maintenance are summarized in Table 1.

Table 1 Experimental Design and Materials and Methods in the Studies of o-Chloropyridine

Two-week Dermal Studies | Three-month Drinking Water Studies
Study Laboratory
BioReliance Corp. (Rockville, MD) | BioReliance Corp. (Rockville, MD)
Strain and Species
F344/N rats B6C3F1/N mice | F344/N rats B6C3F1/N mice
Animal Source
Taconic Farms, Inc. (Germantown, NY) | Taconic Farms, Inc. (Germantown, NY)
Time Held Before Studies
Rats: 12 days Mice: 13 days | Rats: 11 (males) or 12 (females) days Mice: 14 (males) or 15 (females) days
Average Age When Studies Began
5–6 weeks | Rats: 5–6 weeks Mice: 6–7 weeks
Date of First Dose or Exposure
Rats: September 19, 2000 Mice: September 20, 2000 | Rats: July 28, 2003 Mice: July 31, 2003
Duration of Dosing or Exposure
5 exposures per week for 16 days | 14 weeks (core study)
Date of Last Dose or Exposure
Rats: October 4, 2000 Mice: October 5, 2000 | Rats: October 27 (males) or 28 (females), 2003 Mice: October 30 (males) or 31 (females), 2003
Necropsy Dates
Rats: October 5, 2000 Mice: October 6, 2000 | Rats: October 27 (males) or 28 (females), 2003 Mice: October 30 (males) or 31 (females), 2003
Average Age at Necropsy
8–9 weeks | Rats: 18–19 weeks Mice: 19–20 weeks
Size of Study Groups
5 males and 5 females | 10 males and 10 females
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights. | Same as 2-week studies
Animals per Cage
1 animal | Rats: 5 Mice: 1 (males) or 5 (females)
Method of Animal Identification
Tail tattoo | Tail tattoo
Diet
NTP-2000 open formula pelleted diet (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, changed once weekly | Same as 2-week studies
Water
Tap water (Washington, D.C., Suburban Sanitary Commission Potomac Plant) via automatic watering system (Edstrom Industries, Inc., Waterford, WI), available ad libitum | Same as 2-week studies, except via amber glass bottles equipped with stainless steel sipper tubes and neoprene stoppers with screw on polypropylene lids
Cages
Polycarbonate (Lab Products, Inc., Seaford, DE), changed once weekly | Same as 2-week studies; changed twice weekly for rats and female mice and once weekly for male mice; rotated every 2 weeks
Bedding
Irradiated, heat-treated Sani-Chips^®^ (P.J. Murphy Forest Products Corp., Montville, NJ), changed once weekly | Same as 2-week studies; changed twice weekly for rats and female mice and once weekly for male mice
Cage Filters
Remay^®^ 2016 (Snow Filtration, Cincinnati, OH) | Same as 2-week studies
Racks
Stainless steel (Lab Products, Inc., Seaford, DE), changed once every 2 weeks | Same as 2-week studies; changed and rotated once every 2 weeks
Animal Room Environment
Temperature: 72° ± 3°F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Room air changes: 10/hour | Same as 2-week studies
Doses or Exposure
0, 6.25, 12.5, 25, 50, or 100 mg/kg | 0, 10, 30, 100, 300, or 1,000 ppm
Type and Frequency of Observation
Observed twice daily; animals were weighed initially, on day 8, and at the end of the studies; clinical findings were recorded daily. | Observed twice daily; core study animals were weighed and clinical findings were recorded initially, weekly, and at the end of the studies. Water consumption by core study animals was recorded weekly by cage.
Method of Sacrifice
Carbon dioxide asphyxiation | Same as 2-week studies
Necropsy
Necropsies were performed on all animals. Organs weighed were heart, right kidney, liver, lung, right testis, and thymus. | Necropsies were performed on all core study animals. Organs weighed were heart, right kidney, liver, lung, right testis, and thymus.
Clinical Pathology
None | Blood was collected from the retroorbital sinus of clinical pathology study animals on days 4 and 22 and from core study animals at the end of the studies for hematology and clinical chemistry (rats only). Hematology: hematocrit; hemoglobin; erythrocyte, reticulocyte, nucleated erythrocyte, and platelet counts; mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; and leukocyte count and differentials. Clinical chemistry: urea nitrogen, creatinine, total protein, albumin, alanine aminotransferase, alkaline phosphatase, creatine kinase, sorbitol dehydrogenase, and bile acids
Histopathology
Gross lesions were examined. | Complete histopathology was performed on 0 and 1,000 ppm core study rats and mice and a read down was performed when needed. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, eye, gallbladder (mice), Harderian gland, heart and aorta, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, liver, lung (with mainstem bronchus), lymph nodes (mandibular and mesenteric), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle, skin, spleen, stomach (forestomach and glandular), testis (with epididymis), thymus, thyroid gland, trachea, urinary bladder, and uterus. The bone marrow, kidney, liver, and spleen were examined in the remaining groups of core study rats, and the kidney and liver were examined in the remaining groups of mice.
Sperm Motility and Vaginal Cytology
None | At the end of the studies, sperm samples were collected from core study males in the 0, 100, 300, and 1,000 ppm groups for sperm motility evaluations. The following parameters were evaluated: spermatid heads per testis and per gram testis, spermatid counts, and epididymal spermatozoal motility and concentration. The left cauda, left epididymis, and left testis were weighed. Vaginal samples were collected for up to 12 consecutive days prior to the end of the studies from core study females exposed to 0, 100, 300, or 1,000 ppm for vaginal cytology evaluations.

Necropsies were performed on all rats and mice. The heart, right kidney, liver, lung, right testis, and thymus were weighed. Histopathologic examinations were performed on gross lesions in rats; no gross lesions were observed in mice.

## Three-month Drinking Water Studies

For the 3-month studies, the route of exposure was changed from dermal administration to drinking water, allowing for comparison of o-chloropyridine toxicity with the results of the NTP 3-month drinking water studies of a structurally similar compound, pyridine.^33^ Male and female F344/N rats and B6C3F1/N mice were obtained from the NTP colony maintained at Taconic Farms, Inc. (Germantown, NY). On receipt, the rats and mice were 3 weeks old. Animals were quarantined for 11 to 12 days (rats) or 14 to 15 days (mice); rats were 5 to 6 weeks old and mice were 6 to 7 weeks old on the first day of the studies. Upon arrival at the facility, five male and five female rats and mice were randomly selected for parasite evaluation and gross observation for evidence of disease. Additionally, the health of the animals was monitored during the studies according to the protocols of the NTP Sentinel Animal Program (Appendix I). All test results were negative.

The core study animals consisted of groups of 10 male and 10 female rats and mice that were exposed to o-chloropyridine in drinking water at concentrations of 0, 10, 30, 100, 300, or 1,000 ppm for 14 weeks. Exposure concentrations for the 3-month drinking water studies were selected for comparison to the 3-month pyridine study results.^33^ Additional groups of 10 male and 10 female rats designated as clinical pathology study rats were exposed to the same concentrations for 22 days for evaluation of clinical pathology endpoints at days 4 and 22; these animals were not assessed for other endpoints. Clinical pathology results presented for week 14 are from core study animals. Feed and water were available ad libitum. Rats and female mice were housed five per cage and male mice were housed individually. Core study animals were weighed and clinical findings were recorded initially, weekly, and at the end of the studies. Water consumption by core study animals was recorded weekly by cage. Details of the study design and animal maintenance are summarized in Table 1.

Animals were anesthetized with a 70% carbon dioxide:30% oxygen mixture, and blood was collected from the retroorbital sinus of clinical pathology study rats on days 4 and 22 and from core study rats and mice at the end of the 3-month studies for hematology and clinical chemistry (rats only) analyses (Appendix B). Hematology and clinical chemistry parameters were measured using a ABX Pentra C+ Analyzer (Horiba Instruments Corporation, Irvine, CA) and a Hitachi 717 Analyzer (Boehringer Mannheim, Indianapolis, IN), respectively, using reagents supplied by the manufacturers. The parameters measured are listed in Table 1.

At the end of the 3-month drinking water studies, samples were collected for sperm motility and vaginal cytology evaluations on rats and mice exposed to 0, 100, 300, or 1,000 ppm. The parameters evaluated are listed in Table 1. For 12 consecutive days prior to scheduled terminal sacrifice, the vaginal vaults of the females were moistened with saline, if necessary, and samples of vaginal fluid and cells were stained. Relative numbers of leukocytes, nucleated epithelial cells, and large squamous epithelial cells were determined and used to ascertain estrous cycle stage (i.e., diestrus, proestrus, estrus, and metestrus). Male animals were evaluated for sperm count and motility. The left testis and left epididymis were isolated and weighed. The tail of the epididymis (cauda epididymis) was then removed from the epididymal body (corpus epididymis) and weighed. Test yolk (rats) or modified Tyrode’s buffer (mice) was applied to slides and a small incision was made at the distal border of the cauda epididymis. The sperm effluxing from the incision were dispersed in the buffer on the slides, and the numbers of motile and nonmotile spermatozoa were counted for five fields per slide by two observers. Following completion of sperm motility estimates, each left cauda epididymis was placed in buffered saline solution. Caudae were finely minced, and the tissue was incubated in the saline solution and then heat fixed at 65°C. Sperm density was then determined microscopically with the aid of a hemacytometer. To quantify spermatogenesis, the testicular spermatid head count was determined by removing the tunica albuginea and homogenizing the left testis in phosphate-buffered saline containing 10% dimethyl sulfoxide. Homogenization-resistant spermatid nuclei were counted with a hemacytometer.

Necropsies were performed on all core study rats and mice. The heart, right kidney, liver, lung, right testis, and thymus were weighed. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin (eyes were first fixed in Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin. Complete histopathologic examinations were performed by the study laboratory pathologist on core study rats and mice in the 0 and 1,000 ppm groups; the bone marrow, kidney, liver, and spleen of rats and the kidney and liver of mice were examined in the remaining core study groups. If findings were observed in the 1,000 ppm group, a read down was performed in which lower exposure groups were examined until a no-effect level was determined for a given endpoint. Table 1 lists the tissues and organs routinely examined.

After a review of the laboratory reports and selected histopathology slides by a quality assessment (QA) pathologist, the findings and reviewed slides were submitted to a NTP Pathology Working Group (PWG) coordinator for a second independent review. Any inconsistencies in the diagnoses made by the laboratory and QA pathologists were resolved by the NTP pathology peer review process. Final diagnoses for reviewed lesions represent a consensus of the PWG or a consensus between the study laboratory pathologist, NTP pathologist, QA pathologist(s), and the PWG coordinator. Details of these review procedures have been described, in part, by Maronpot and Boorman^34^ and Boorman et al.^35^

## Statistical Methods

### Calculation and Analysis of Lesion Incidences

The incidences of lesions are presented in Appendix A as the numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. The Fisher exact test,^36^ a procedure based on the overall proportion of affected animals, was used to determine significance.

### Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between dosed or exposed and control groups in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^37^ and Williams.^38,39^ Hematology, clinical chemistry, spermatid, and epididymal spermatozoal data, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley^40^ (as modified by Williams^41^), and Dunn.^42^ Jonckheere’s test^43^ was used to assess the significance of the dose-related trends and to determine whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic dose-related trend (Dunnett’s or Dunn’s test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey^44^ were examined by NTP personnel, and implausible values were eliminated from the analysis. Proportions of regular cycling females in each exposed group were compared to the control group using the Fisher exact test.^36^ Tests for extended periods of estrus, diestrus, metestrus, and proestrus, as well as skipped estrus and skipped diestrus were constructed based on a Markov chain model proposed by Girard and Sager.^45^ For each exposure group, a transition probability matrix was estimated for transitions among the proestrus, estrus, metestrus, and diestrus stages, with provision for extended stays within each stage as well as for skipping estrus or diestrus within a cycle. Equality of transition matrices among exposure groups and between the control group and each exposed group was tested using chi-square statistics.

## Quality Assurance Methods

The 2-week and 3-month studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations.^46^ In addition, as records from the 3-month studies were submitted to the NTP Archives, these studies were audited retrospectively by an independent QA contractor. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Toxicity Study Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Toxicity Study Report.

## Genetic Toxicology

### Salmonella typhimurium Mutagenicity Test Protocol

Testing was performed as reported by Zeiger et al.^47^ o-Chloropyridine was sent to the laboratory as a coded aliquot. It was incubated with the Salmonella typhimurium tester strains TA98 and TA100 either in buffer or S9 mix (metabolic activation enzymes and cofactors from Aroclor 1254-induced male Sprague-Dawley rat or Syrian hamster liver) for 20 minutes at 37°C. Top agar supplemented with l-histidine and d-biotin was added, and the contents of the tubes were mixed and poured onto the surfaces of minimal glucose agar plates. Histidine-independent mutant colonies arising on these plates were counted following incubation for 2 days at 37°C.

Each trial consisted of triplicate plates of concurrent positive and negative controls and five doses of o-chloropyridine. The assay limit dose was 10,000 µg/plate. All positive trials were repeated under the conditions that elicited the positive response.

In this assay, a positive response is defined as a reproducible, dose-related increase in histidine-independent (revertant) colonies in any one strain/activation combination. An equivocal response is defined as an increase in revertants that is not dose related, is not reproducible, or is not of sufficient magnitude to support a determination of mutagenicity. A negative response is obtained when no increase in revertant colonies is observed following chemical treatment. There is no minimum percentage or fold increase required for a chemical to be judged positive or weakly positive, although positive calls are typically reserved for increases in mutant colonies that are at least twofold over background.

### Mouse Peripheral Blood Micronucleus Test Protocol

A detailed discussion of this assay is presented by MacGregor et al.^48^ At the end of the 3-month toxicity study, peripheral blood samples were obtained from male and female mice. Smears were immediately prepared and fixed in absolute methanol. The methanol-fixed slides were stained with acridine orange and coded. Slides were scanned to determine the frequency of micronuclei in 2,000 normochromatic (mature) erythrocytes (NCEs) in each of five animals per exposure group. In addition, the percentage of polychromatic erythrocytes (PCEs; reticulocytes) in a population of 1,000 erythrocytes was scored for each dose group as a measure of bone marrow toxicity.

The results were tabulated as the mean of the pooled results from all animals within a treatment group plus or minus the standard error of the mean. The frequency of micronucleated cells among NCEs was analyzed by a statistical software package that tested for increasing trend over exposure groups with a one-tailed Cochran-Armitage trend test, followed by pairwise comparisons between each exposed group and the control group. In the presence of excess binomial variation, as detected by a binomial dispersion test, the binomial variance of the Cochran-Armitage test was adjusted upward in proportion to the excess variation. In the micronucleus test, an individual trial is considered positive if the trend test P value is less than or equal to 0.025 or if the P value for any single exposed group is less than or equal to 0.025 divided by the number of exposed groups. Ultimately, the final call is determined by the scientific staff after considering the results of statistical analyses, the reproducibility of any effects observed, and the magnitudes of those effects.

### Evaluation Protocol

These are the basic guidelines for arriving at an overall assay result for assays performed by the National Toxicology Program. Statistical as well as biological factors are considered. For an individual assay, the statistical procedures for data analysis have been described in the preceding protocols. There have been instances, however, in which multiple samples of a chemical were tested in the same assay, and different results were obtained among these samples and/or among laboratories. Results from more than one aliquot or from more than one laboratory are not simply combined into an overall result. Rather, all the data are critically evaluated, particularly with regard to pertinent protocol variations, in determining the weight of evidence for an overall conclusion of chemical activity in an assay. In addition to multiple aliquots, the in vitro assays have another variable that must be considered in arriving at an overall test result. In vitro assays are conducted with and without exogenous metabolic activation. Results obtained in the absence of activation are not combined with results obtained in the presence of activation; each testing condition is evaluated separately. The summary table in the Abstract of this Toxicity Study Report presents a result that represents a scientific judgment of the overall evidence for activity of the chemical in an assay.