# Introduction

Figure 1

o-Chloropyridine (CASRN 109-09-1; Chemical Formula: C_5_H_4_ClN; Molecular Weight: 113.55)

Synonyms: Alpha-chloropyridine; 2-chloro-(9Cl); 2-chloropyridine (8Cl); pyridines.

## Chemical and Physical Properties

o-Chloropyridine is a colorless, oily liquid with a density of 1.205 g/cm^3^ at 15°C^1,2^ and a boiling point of 170°C.^1^ The water solubility of o-chloropyridine is 2.5 g/100 g at 25°C; o-chloropyridine is soluble in alcohol and ether.^2,3^ o-Chloropyridine poses a slight fire hazard, and when exposed to heat can release toxic phosgene gas.^1,4^

## Production, Use, and Human Exposure

o-Chloropyridine can be prepared by direct chlorination of pyridine in the vapor phase (>300°C) in the presence of a diluent.^5^ One patented process (Reilly Industries, Inc.) involves selective chlorination of pyridine with chlorine in nitrogen in the presence of water vapor; synthesis occurs in two stages at 470° and 290°C.^6^ o-Chloropyridine is prepared for use as an intermediate by heating potassium pyrrole with chloroform. Another patented process involves the reaction of alpha-picoline with chlorine in the gas phase in the presence of water and a catalyst, such as pyrophyllite; this process yields a mix of chlorinated pyridines.^7^ A third patented process reacts 2-hydroxypyridine with phosgene in the presence of an amide, such as N,N-dimethylformamide.^8^

o-Chloropyridine is listed as a chemical in commerce in the United States; no production or sales quantities were listed to avoid disclosure of the single producer’s operations.^9^ Companies are required to report production of 10,000 pounds or more or sales of $10,000 or more. The United States Environmental Protection Agency^10^ lists o-chloropyridine in its Toxic Substances Control Act inventory. In 2006, the production and import of o-chloropyridine in the United States was reported to range from 1 million to 10 million pounds.^11^

o-Chloropyridine is used as an intermediate in synthetic organic, pharmaceutical, and agricultural chemical (fungicides, herbicides) manufacturing. It is also used as a catalyst for phase transfer.^1,12^ It is a key intermediate in the manufacture of pyrithione-based biocides for use in cosmetics and various pharmaceutical products.^13^ o-Chloropyridine is used as a starting material in the production of the antihistamine, pheniramine, and the antiarrhythmic, diisopyramide.^5^ o-Chloropyridine is available in purified (99%), technical (95%), or crude (80%) grades.^3,12,14-16^

There is potential for occupational exposure to o-chloropyridine during its production and use as an industrial chemical intermediate. A survey of the Olin Corporation plant in Rochester, NY, noted that significant exposures to chemicals in the o-chloropyridine processing area existed and that high vapor concentrations resulting from liquid spills and minor leaks were detected in the closed processing area, and quarterly sampling of personnel to detect exposures was recommended.^17^ o-Chloropyridine is not listed in the National Occupational Exposure Survey.^18^

Gehring et al.^19^ noted that the solubility of o-chloropyridine in organic solvents suggests that it might have high dermal absorption and subsequently, Gehring^4^ reported experimental evidence that chlorinated pyridines are rapidly absorbed through intact skin.

o-Chloropyridine has not been reported to occur naturally; however, it is reported to be an environmental contaminant. The Dow Chemical Company has identified it as a trace organic chemical in process streams and wastewater.^20^ It has also been identified as a Rhine River pollutant in the Netherlands (0.023 µg/L) and a trace organic contaminant (detected, not quantified) in drinking water derived from river water in Barcelona, Spain.^21,22^

o-Chloropyridine was detected as an intermediate product in amended freshwater sediment slurries; it arose from the biotransformation of 2,3-dichloropyridine under anaerobic (methanogenic) conditions. It was reported to be persistent and not to be further metabolized during a 6-month incubation period.^23^ Adrian and Suflita^24^ reported that o-chloropyridine resisted biodegradation in anoxic aquifer slurries incubated for 11 months.

## Regulatory Status

No standards or guidelines have been set by the National Institute for Occupational Safety and Health or the Occupational Safety and Health Administration for occupational exposure or workplace maximum allowable levels of o-chloropyridine. The American Conference of Governmental Industrial Hygienists has not recommended a threshold limit value or biological exposure index for this compound.^25^ o-Chloropyridine is classified as a poisonous material by the U.S. Department of Transportation.^26^ The USEPA^17^ has issued a requirement for health and safety data reporting on pyridine and pyridine derivatives, including o-chloropyridine.

## Absorption, Distribution, and Metabolism

Incubation of o-chloropyridine with liver homogenate and cofactors yielded o-chloropyridine-N-oxide and pyridine-N-oxide.^27^ No disposition or metabolism studies of o-chloropyridine in experimental animals or humans could be found in the literature.

## Toxicity

### Experimental Animals

The acute toxicity of o-chloropyridine has been studied in mice, rats, and rabbits.^19^ The mouse oral LD50 is 100 mg/kg, and the intraperitoneal LD50 is 130 mg/kg. Gross lesions included swollen and fatty livers as well as hemorrhage and necrosis at higher doses and swollen, edematous kidneys in some animals. Concurrent administration of methionine had a protective effect against toxicity, while cysteine and nicotinamide enhanced the toxicity of o-chloropyridine. In rabbits, o-chloropyridine was essentially as toxic when applied to the skin as when given by intraperitoneal injection. The rabbit dermal LD50 is 64 mg/kg and the intraperitoneal LD50 is 48 mg/kg. The primary gross lesion, regardless of route of administration, was hemorrhagic necrosis of the liver. Instillation of undiluted or 10% o-chloropyridine solution in propylene glycol in the eyes of rabbits caused severe inflammation of the conjunctiva and moderate clouding of the cornea that persisted for 48 hours.

### Humans

o-Chloropyridine was reported to be a skin irritant and toxic by ingestion.^1,14^

## Reproductive and Developmental Toxicity

No reproductive or developmental toxicity studies of o-chloropyridine in animals or humans were identified in the literature.

## Carcinogenicity

No 2-year carcinogenicity studies of o-chloropyridine in animals or epidemiological studies or case reports investigating the association of exposure to o-chloropyridine and cancer risk in humans were identified in the literature.

## Genetic Toxicity

o-Chloropyridine was mutagenic in Salmonella typhimurium strains TA97, TA98, TA100, and TA102 in tests conducted with exogenous metabolic activation (S9 liver enzymes), but no mutagenicity was detected in any of the strains without activation.^27,28^ Zimmerman et al.^29^ reported weak induction of aneuploidy in the yeast Saccharomyces cerevisiae treated with o-chloropyridine concentrations up to 0.50%.

Tests in mammalian cells showed no induction of chromosomal aberrations by o-chloropyridine in African green monkey kidney cells (V3) in the absence of S9 enzymes.^30^ However, when V3 cells were treated with 1,600 µg/mL o-chloropyridine in the presence of pyridine N-oxide, 25% of the cells were chromosomally aberrant; pyridine N-oxide (200 µg/mL) alone was not clastogenic in V3 cells.^30^

In contrast to the results in V3 cells, o-chloropyridine was reported to induce gene mutations, chromosomal aberrations, and micronuclei in L5178Y mouse lymphoma cells with and without metabolic activation (rat liver S9 enzymes); the gene mutation and chromosomal aberration responses were stronger in the presence of S9.^31^ These results led Dearfield et al.^31^ to postulate that substitution at the o-position promotes genotoxic effects of the halogenated pyridines through N-oxidation by microsomal enzymes. This mechanism was also explored in experiments conducted by Chłopkiewicz et al.^27^ and designed to investigate the effects of N-oxidation and OH radicals on the mutagenicity of o-chloropyridine in S. typhimurium TA100; they reported mutagenicity in a plate incorporation method in TA100 only with S9 and no, or greatly reduced, mutagenicity when glutathione, thiourea, D-mannitol, or pyridine N-oxide was added to the test mixture.

The metabolite o-chloropyridine N-oxide was not mutagenic in S. typhimurium strain TA100, with or without S9, when tested using a plate incorporation protocol.^27^

The structurally related compound, 3-chloropyridine, was not mutagenic in S. typhimurium strains TA97, TA98, TA100, or TA102, with or without S9 metabolic activation.^28,32^ 3-Chloropyridine induced a dose-related increase in chromosomal aberrations in V3 cells in the absence of S9^30^; clastogenicity was eliminated when cultures were incubated in the presence of pyridine N-oxide. 3-Chloropyridine induced small increases in gene mutations and chromosomal aberrations in mouse lymphoma L5178Y cells,^31^ with and without S9 metabolic activation; micronuclei were induced by 3-chloropyridine only in the absence of S9.

## Study Rationale

o-Chloropyridine was nominated for testing by NTP based on increasing production and use as a site-limited pharmaceutical and agrochemical intermediate, the potential for occupational and environmental exposures during its manufacture, its persistence in the environment (lasting longer than 6 months), evidence of mutagenicity based on results of several short-term test systems, and suspicion of carcinogenicity based on structure and evidence of mutagenic or carcinogenic effects associated with structurally related chemicals. Dermal exposure was selected for the 2-week studies based on the likely route of occupational exposure. The route of exposure was changed to oral, via drinking water, in the 3-month studies due to concerns regarding skin irritation following longer dermal exposure and to allow comparison of o-chloropyridine toxicity with the results of the NTP 3-month drinking water studies of a structurally similar compound, pyridine.^33^