# Appendix J Absorption, Distribution, Metabolism, Excretion, and Toxicokinetics

## J.1 Introduction

The objective of these studies was to determine the disposition and metabolism of o-chloropyridine in male F344 rats after a single oral gavage administration of 0.1 or 10 mg/kg of o-chloropyridine. Limited studies were also conducted following intravenous and intraperitoneal dosing. Concentration of parent compound or the total radioactivity was also determined in blood in order to establish basic toxicokinetic parameters. Attempts were also made to identify metabolites of o-chloropyridine in rat urine and bile after a single oral or intraperitoneal dose.

## J.2 Materials and Methods

### J.2.1 Chemicals

Nonradiolabeled o-chloropyridine (CAS No. 109-09-1, purity 99%, lot 03721) was purchased from Aldrich Chemical Company, Inc. (Milwaukee, WI). The identity of nonradiolabeled o-chloropyridine was confirmed by mass spectrometry (MS). The position of the chloro substituent was confirmed by chromatographic resolution of isomeric mono- and dichloropyridine standards using high-performance liquid chromatography (HPLC).

o-Chloropyridine radiolabeled with ^14^C in the 2 and 6 positions (lot 3228-292, specific activity 58.50 mCi/mmol), in an ethanol solution was received from New England Nuclear Corporation (Boston, MA).

Structure of [^14^C]-o-chloropyridine (*denotes position of ^14^C)

The radiochemical purity of the test material was determined to be equal to or higher than 95% by HPLC.

Prospective metabolites of o-chloropyridine, N-methylpyridine-2-mercapturic acid, pyridine-N-oxide-2-mercapturic acid, 2-methylthiopyridine, 2-methylthiopyridine-N-oxide, 2-chloro-5-pyridinol, and 2-chloro-4-pyridinol were synthesized in-house using methods of Talik,^58^ Beak and Lee,^59^ Westland et al.,^60^ and Kohrman et al.^61^

### J.2.2 Animals

Young adult male F344 rats were obtained from Charles River Laboratories, Inc. (Raleigh, NC), and were quarantined for at least 1 week prior to the start of the study. Animals were fed certified Purina Rodent Chow (5002; Purina Mills, Inc., St. Louis, MO) and furnished tap water ad libitum. During acclimation (1 day prior to dosing) and following dosing, metabolism study animals were housed individually in metabolism chambers that provided for separate collection of urine, feces, and volatiles. Biliary excretion study rats were kept on heating pads to maintain body temperature throughout the study. Toxicokinetic study rats were housed individually in cages following surgical implantation of the jugular cannulae and throughout the toxicokinetic study. In the animal rooms, air circulation was 100% fresh filtered, room temperature was maintained at 64° to 79°F, and relative humidity ranged from 30% to 70%. Light and darkness were cycled at 12-hour intervals.

Anesthesia was used to avoid undue pain or distress. Rats were anesthetized with ketamine/xylazine (7:1, 50 to 80 mg/kg intramuscular or to effect) prior to surgical implantation of the jugular cannula^62^ for toxicokinetic studies. Biliary excretion study rats were anesthetized with sodium pentobarbital, orally (35 mg/kg) and intraperitoneally (45 mg/kg), prior to cannulation of the bile duct. A state of anesthesia was maintained throughout the bile collection period by injection of sodium pentobarbital (5 mg/kg) as needed. At the end of the oral gavage studies, rats were euthanized by exsanguination and section of the diaphragm. Toxicokinetic and biliary excretion study rats were euthanized by CO_2_ overexposure after the final collection.

### J.2.3 Study Design

Absorption, distribution, metabolism, and excretion of o-chloropyridine were investigated in groups of rats following a single oral gavage dose of either 0.1 or 10 mg [^14^C]-o-chloropyridine/kg body weight (10 µCi per animal) and killed 72 hours following dosing. Toxicokinetics of o-chloropyridine was investigated in jugular vein-cannulated rats receiving a single oral gavage dose of 10 mg/kg or a single intravenous injection of 1 mg/kg (30 µCi per animal in each case). Biliary excretion and metabolism were investigated in rats receiving a single intraperitoneal injection of 50 mg/kg (35 µCi per animal) for bile collection for up to 4 hours.

For all studies, formulations were prepared by addition of Alkamuls^®^ EL-620/L (no more than 15% of the dose) (Rhodia, Inc., Cranbury, NJ) to known amounts of o-chloropyridine following which distilled deionized water and the appropriate amount of [^14^C]-o-chloropyridine were added. Dosing volumes were either 5 mL/kg (oral gavage and intraperitoneal injection or 1 mL/kg (intravenous injection). Oral doses were administered by intragastic gavage using a syringe equipped with a 16-gauge gavage needle. Intravenous doses were injected into a lateral tail vein using a syringe equipped with a 27-gauge needle.

### J.2.4 Sample Collection

In mass balance studies, urine and feces were collected separately into containers cooled with dry ice for up to 72 hours. At terminal kill, urine was collected directly from the bladder and added to the final urine collection. After terminal kill, the cages were rinsed well with water and ethanol. Urine, feces, and cage rinse collections were stored in the dark at −20°C until analyzed. Volatiles were collected by passing air from the metabolism chamber through a series of traps containing ethanol and 1 N NaOH for collection of volatile organics and CO_2_, respectively.

At terminal kill, blood from anesthetized rats was collected into a heparinized syringe by cardiac puncture. Duplicate samples of skin (ears), triplicate samples of muscle (hind leg and abdominal) and adipose tissue (perirenal and epididymal), and the entire kidneys, liver, spleen, lungs, testes, bladder, heart, and brain were removed. The stomach, small intestine, cecum, and large intestine (all included contents) were removed and the carcasses were stored.

Bile was collected via a bile duct cannula extension for up to 4 hours postdosing. Bile collections were stored at −80°C prior to analysis.

In toxicokinetic studies, blood samples were collected from rats via a jugular cannula for up to 72 hours postdosing (oral gavage study) and for up to 4 hours postdosing (intravenous injection study). In the rat intravenous injection study, the volume of blood withdrawn at each time point was replaced with plasma obtained from donor animals. Blood samples in these studies were extracted immediately after collection as described below.

### J.2.5 Sample Analysis

Whole blood samples (approximately 300 µL per animal per time point) from toxicokinetic studies were extracted three times with twice the volume of hexanes. The three extracts from each sample were pooled and stored at −20°C prior to analysis for total radioactivity and for parent o-chloropyridine (intravenous studies only) by HPLC as described below.

Radioactivity in samples was measured by liquid scintillation spectrophotometry (LSS). Ultima Gold^TM^ scintillation cocktail (Packard Instrument Company, Meriden, CT) was used in all determinations of radiochemical content. Duplicate aliquots of urine, duplicate aliquots of bile, triplicate aliquots of cage rinse and trapping solutions from breath traps, and duplicate aliquots of blood extracts were directly analyzed. Triplicate samples of feces were weighed, homogenized with equal amounts of water, and solubilized in Soluene^®^-350 (Packard Instrument Company). Tissue samples (from large tissues) and small tissues and organs in their entirety were digested in Soluene^®^-350. Large organs like the liver were homogenized, and weighed aliquots of the homogenate were used. Blood samples were neutralized and decolorized by treatment with perchloric acid and H__2__O__2__ prior to solubilization. Gastrointestinal tract tissues and carcass were digested in 2 N ethanolic NaOH prior to analysis of triplicate aliquots for radioactivity.

### J.2.6 Metabolic Profiling and Identification

Aliquots of the 1-hour and 4-hour bile collections were mixed with an equal amount of the initial-condition mobile phase containing 0.1% trifluoroacetic acid (TFA) and the mixture was centrifuged prior to analysis by HPLC (see below). An aliquot of bile was also incubated with β-glucuronidase type VII-A, obtained from Escherichia coli for 17 hours at 37°C, and centrifuged prior to HPLC analysis.

Composite urine samples (0 to 24 hours) from the 10 mg/kg oral gavage study were profiled using HPLC. Urine was subjected to acid hydrolysis to determine whether acid labile conjugates were present. Urine was hydrolyzed by addition of 1 N HCl followed by heating overnight between 50° and 55°C. After hydrolysis, the samples were neutralized and analyzed by HPLC/LSS.

Radiolabeled urinary metabolites were isolated using HPLC as described below. Fractions containing the same metabolites collected from a number of injections were pooled and concentrated. Other chromatographic conditions were then developed for the separation of the urinary metabolites in the fractions containing multiple radiolabeled components. Selected fractions were analyzed by MS and nuclear magnetic resonance (NMR) spectroscopy for identification of metabolites.

### J.2.7 High-Performance Liquid Chromatography

The HPLC system consisted of two Waters pumps (models 515, 510, or 6000A; Waters Corporation, Milford, MA) or a Waters 600E solvent delivery system, a Rheodyne Model 7125 injector (Rheodyne, LLC, Rohnert Park, CA), an ABI 759A absorbance detector (set at 230 or 254 nm; Applied Biosystems, Inc., Foster City, CA) or a Waters 2487 dual absorbance detector (set at 250 and 285 nm), and a βRAM-LS radioactivity detector equipped with a 200-, 250-, or 500-µL lithium glass flowthrough solid scintillator flow cell. The flow rate was 1 mL/minute unless otherwise specified. Column effluent was collected in timed fractions and assayed for [^14^C] content using LSS.

Blood extracts for o-chloropyridine levels were analyzed on an Alltech^®^ Alltima^TM^ Cyano 100-Å column (250 mm × 4.6 mm, 5 µm particle size; Alltech Associates, Inc., Deerfield, IL). The analysis was isocratic with a mobile phase consisting of 95:5 (v:v) hexanes:ethanol.

Profiling of urinary metabolites was done on a Phenomenex^®^ Luna^®^ C18 column (150 mm × 4.6 mm, 5 µm particle size; Phenomenex, Inc., Torrance, CA) using acetonitrile and water, both containing 0.1% TFA. The acetonitrile gradient was linearly increased as follows: 2% for 5 minutes, to 10% over 15 minutes, and then to 50% over 5 minutes. Acid-hydrolyzed urine samples were analyzed the same way except that the gradient was changed from 2% to 20% over 15 minutes.

Further profiling of the urinary metabolites and profiling of bile utilized a Phenomenex^®^ Aqua^®^ C18 column (250 mm × 4.6 mm, 5 µm particle size); the mobile phases used were 100% 0.05 M ammonium acetate buffer, pH 4, and acetonitrile. Urine was eluted with a linear gradient from 0% to 75% acetonitrile over 30 minutes. Bile was eluted with water and acetonitrile, both containing 0.1% TFA, at a flow rate of 2 mL/minute. The acetonitrile gradient was linearly increased as follows: 3% for 2 minutes, to 11% over 16 minutes, to 25% over 6 minutes, and then to 90% over 2 minutes. For the isolation of biliary metabolites, the same mobile phase gradient was run at a flow rate of 4 mL/minute on a Phenomenex^®^ Aqua^®^ C18 column (250 mm × 10 mm, 5 µm particle size).

Urinary metabolites were isolated using a Phenomenex^®^ Aqua^®^ C18 column (250 mm × 10 mm, 5 µm particle size) using acetonitrile and water, both containing 0.1% TFA. The acetonitrile gradient was linearly increased as follows: 3% for 5 minutes, to 10% over 20 minutes, to 15% over 5 minutes, and then to 90% over 2 minutes. The flow rate was 4 mL/minute. Variations of this method using isocratic conditions of 8%, 10%, 20%, or 25% acetonitrile were used to further purify the urine fractions as necessary.

Analysis of urinary fractions for metabolite identification by LC/MS used a Phenomenex^®^ Aqua^®^ C18 column (250 mm × 4.6 mm, 5 µm particle size). The mobile phases used were acetonitrile and water, both containing 0.1% TFA at isocratic conditions of 20%, 30%, 40%, or 60% acetonitrile and a flow rate of 0.5 mL/minute.

### J.2.8 Other Instrumentation

NMR spectra were obtained using a Bruker^®^ AMX-500 NMR spectrometer (Bruker BioSpin Corporation, Newark, DE) and a Bruker^®^ AVANCE^TM^-300 spectrometer. Mass spectra were obtained using a Hewlett Packard 6890 Series capillary gas chromatograph (Hewlett-Packard Company, Palo Alto, CA) and a HP 5973 mass selective detector or on a PE SCIEX API 150 EX analyzer (Perkin Elmer Sciex, Wellesley, MA) attached to an Agilent 110 Series Tower (Agilent Technologies) with an IN/US PRAM (IN/US Systems, Inc., Tampa, FL) inline.

### J.2.9 Toxicokinetic Analysis

Blood concentration-time data were analyzed by model-dependent methods using WinNonlin^®^ version 1.0 (Pharsight Corporation, Mountain View, CA). Three different methods of weighting the data points (uniform, 1/y, and 1/y^2^) were utilized. A statistical F test was used for the selection of the appropriate number of compartments for the best-fit model. The two-compartment model resulted in the best fits to the blood o-chloropyridine concentration-time data in rats after intravenous injection. The data for one rat were poorly fitted by the simulation at the last two time points. For this reason, this rat was excluded from the analysis. The two-compartment model is described by the following equation:

C(t) = A×e^−αt^ + B×e^−βt^

where constants A and B are intercepts on the y axis for each exponential segment of the curve and β and α are the elimination and distribution rate constants, respectively.

## J.3 Results and Discussion

### J.3.1 Metabolism and Disposition of o-Chloropyridine

Disposition data for rats receiving a single oral gavage dose of 10 mg [^14^C]-o-chloropyridine/kg body weight are presented in Table J-1. As shown in the table, 81.9% of the dose was recovered after 72 hours with 35.9% in the urine, 28.4% in the feces, and 12.5% and 1.14%, respectively, as CO_2_ and as volatile organics. Tissue distribution of radiolabel in the same animals is shown in Table J-2. Approximately 0.5% and 3.4% of the dose was found in the residual carcass and selected tissues, respectively, at 72 hours after dosing. The liver and kidney were the only tissues that were found to have appreciable tissue:blood ratios. Data for rats receiving a single oral gavage dose of 0.1 mg/kg [^14^C]-o-chloropyridine show that there are no dose-related differences in the excretion pattern; approximately 38.3%, 28%, 10.5%, and less than 1% was excreted in urine, in feces, as CO_2_, and as volatile organics, respectively (Table J-3 and Table J-4).

The biliary excretion study conducted in rats following a single intraperitoneal injection of 50 mg/kg [^14^C]-o-chloropyridine showed that approximately 27% of the dose was excreted in bile within 4 hours after dosing (Table J-5). Because only 8% of a 50 mg/kg intaperitoneal dose of [^14^C]-o-chloropyridine was excreted in feces within 24 hours in a pilot study (data not shown), a significant recirculation of the dose from the lower gastrointestinal tract can be expected.

A profile of urine from oral gavage administration is shown in Figure J-1. At least nine peaks were detected of which several were not retained by reverse phase chromatography, but did not cleave by acid hydrolysis. Less than 1% of the recovered ^14^C eluted at the retention time for the parent compound suggesting significant metabolism of o-chloropyridine following oral gavage administration. Based on the metabolism of other pyridines,^63-65^ the urinary excretion of several metabolites was anticipated. Metabolism may include C- and N-oxidation with some conjugation possible. N-Methylation is a significant route of metabolism of pyridine compounds in certain species, including the rat.^66^

Urinary metabolite fractions were isolated using semipreparative HPLC for further characterization. Analyses of three major fractions by NMR spectroscopy and MS indicated disubstituted pyridine structures. Data from a proton NMR spectrum substantiated the structure for one metabolite to contain a mercapturic acid as one substituent and a hydroxyl group as the other substituent on the pyridine ring (Figure J-2). However, it was uncertain whether the hydroxyl group was located at the 4 or 5 position on the pyridine ring. Mass spectral and proton NMR data indicated the structures for two other metabolites to be consistent with hydroxylated o-chloropyridines. One of these was confirmed to be 2-chloro-5-hydroxypyridine by comparison with a synthetic standard (Figure J-2). For the other metabolite, the position of the hydroxyl substitution could not be confirmed (Figure J-2). The HPLC retention time and proton NMR spectra of the third metabolite did not match with those of a synthetic standard of 2-chloro-4-pyridinol (Figure J-2).

Profiling bile after a single intraperitoneal injection of 50 mg/kg [^14^C]-o-chloropyridine showed that the excretion of metabolites in bile was less complex than in urine following oral exposure potentially due to route and/or matrix differences. Incubation of the chromatographically separated bile fractions with β-glucuronidase obtained from E. coli showed shifts in six of the eight metabolite fractions analyzed, indicating the presence of several glucuronide metabolites (results not shown).

### J.3.2 Toxicokinetics

o-Chloropyridine radioactive equivalents in blood (ng-equivalents/g blood) over time in male rats given a single gavage dose of 10 mg [^14^C]-o-chloropyridine/kg body weight are presented in Table J-6. The blood concentration versus time data and estimated toxicokinetic parameters are shown in Figure J-3. Absorption of o-chloropyridine following gavage administration was rapid with a rapid decrease in the concentration of radiolabel (o-chloropyridine equivalents) in blood. The data were best fit using a two-compartment model. The maximum concentration was reached within 30 minutes. The estimated distribution (t_1/2α_) and elimination (t_1/2β_) half-lives, based on the total radioactivity, were 1.14 and 46 hours, respectively.

The blood concentrations of o-chloropyridine (ng/g blood) versus time in rats after a single intravenous injection of 1 mg/kg [^14^C]-o-chloropyridine are shown in Table J-7 and Figure J-4. The maximum concentration of o-chloropyridine in blood, 567 ng/g, was measured at the earliest collection time (0.083 hours postdose). By 3 hours postdosing, the concentration of o-chloropyridine in the blood was too low to detect. A two-compartment model resulted in the best fits to the blood o-chloropyridine concentration-time data. (Data from one rat was poorly fitted by the simulation at the last two time points. For this reason, data for this rat was excluded from the calculation of the mean elimination half-life.) The distribution half-life (t_1/2α_) of o-chloropyridine in the blood was a very rapid 0.103 hours. The elimination half-life (t_1/2β_) of o-chloropyridine in the blood was 1.04 hours (Figure J-4).

## J.4 Summary

The objectives of these studies were to determine disposition and metabolism of o-chloropyridine in male rats after a single oral or injected (i.e., intravenous or intraperitoneal) dose and also to obtain basic toxicokinetic parameters following gavage and intravenous administration in male rats. Excretion and disposition studies were conducted in rats with oral gavage doses of 0.1 and 10 mg/kg [^14^C]-o-chloropyridine. Results were comparable between the two doses indicating no dose-related difference in disposition. Absorption of o-chloropyridine following gavage administration was rapid with the maximum blood concentration reached within 30 minutes. Approximately 82% of the radiolabeled dose was recovered within 72 hours in both studies: 36% to 39% of the dose was excreted in the urine, 28% in feces, 10% to 13% was eliminated as CO_2_, and approximately 1% was excreted as volatile organics. The only tissues with appreciable tissue:blood ratios were the liver and the kidney. The estimated distribution (t_1/2α_) and elimination (t_1/2β_) half-lives in blood, based on the total radioactivity, were 1.14 and 46 hours, respectively. Attempts were made to identify three urinary metabolites that comprised a large percentage of total radioactivity eluted in urine. Data from NMR spectroscopy and MS analyses indicated disubstituted pyridine structures. One of the metabolites contained mercapturic acid as one substituent and a hydroxyl group as the other, although it was uncertain as to whether the hydroxyl group was located at the 4 or 5 position on the pyridine ring. Data for the other two metabolites are consistent with hydroxylated o-chloropyridines, one of which was confirmed as 2-chloro-5-hydroxypyridine by comparison with a synthetic standard. Approximately 27% of a single intraperitoneal dose of

50 mg/kg was excreted in bile within 4 hours of dosing. Incubation of HPLC-fractionated bile with β-glucuronidase obtained from E. coli showed shifts in six of the eight metabolite fractions indicating the presence of several glucuronide metabolites.

Table J-1 Disposition of Radioactivity in Male F344 Rats 72 Hours Following a Single Oral Gavage Dose of 10 mg/kg [^14^C]-o-Chloropyridine^a^

End of Collection Period (Hours) | Urine | Feces | Exhaled CO_2_ | Volatile Organics | Total
6 | 16.3 ± 3.8 | –^b^ | 4.38 ± 0.61 | 0.954 ± 0.298 | 21.6 ± 4.0
12 | 26.0 ± 2.5 | 3.43 ± 4.7 | 9.36 ± 1.04 | 1.06 ± 0.31 | 39.8 ± 4.7
24 | 32.0 ± 1.8 | 25.0 ± 2.3 | 11.3 ± 1.2 | 1.11 ± 0.33 | 69.4 ± 2.6
48 | 34.8 ± 1.5 | 28.0 ± 2.6 | 12.1 ± 1.2 | 1.13 ± 0.33 | 76.0 ± 2.8
72 | 35.9 ± 1.6^c^ | 28.4 ± 2.5 | 12.5 ± 1.2 | 1.14 ± 0.33 | 78.0 ± 3.0
Disposition Summary
Excreta | | | | | 78.0 ± 3.0
Residual Carcass^d^ | | | | | 0.485 ± 0.093
Tissues^e^ | | | | | 3.43 ± 2.9
Total Dose Recovered | | | | | 81.9 ± 2.9

^a^ Data are presented as cumulative percentage of the dose (mean ± standard deviation) for five rats.

^b^ No collection was scheduled for this time interval.

^c^ Includes cage rinse.

^d^ Percent dose recovered in the residual carcass less the percent dose measured in individual tissues: adipose, blood, muscle, and skin.

^e^ Percent dose recovered in the following tissues: adipose, bladder, blood, brain, heart, kidney, liver, lung, muscle, skin, spleen, and testis. Also included were cecum, large and small intestine, and stomach, all with contents.

Table J-2 Tissue Distribution of Radioactivity in Male F344 Rats 72 Hours Following a Single Oral Gavage Dose of 10 mg/kg [^14^C]-o-Chloropyridine^a^

Tissue | o-Chloropyridine Equivalents in Tissue (ng-Eq/g Tissue) | Tissue:Blood Ratio | Dose in Total Tissue (%)^b^
Adipose^c^ | 140 ± 84 | 0.417 ± 0.270 | 0.0910 ± 0.0545
Bladder | 524 ± 57 | 1.53 ± 0.25 | 0.00185 ± 0.00038
Blood | 346 ± 35 | Unity | 0.167 ± 0.018
Brain | 101 ± 10 | 0.293 ± 0.033 | 0.00646 ± 0.00134
Cecum^d^ | NA | NA | 0.0826 ± 0.0087
Heart | 364 ± 39 | 1.06 ± 0.16 | 0.0110 ± 0.0014
Intestine, Large^d^ | NA | NA | 0.0652 ± 0.0144
Intestine, Small^d^ | NA | NA | 0.106 ± 0.007
Kidney | 2,500 ± 309 | 7.27 ± 0.94 | 0.176 ± 0.007
Liver | 3,660 ± 471 | 10.6 ± 1.5 | 1.47 ± 0.15
Lung | 442 ± 34 | 1.29 ± 0.15 | 0.0158 ± 0.0014
Muscle^c^ | 153 ± 18 | 0.445 ± 0.056 | 0.682 ± 0.083
Skin, Ear | 291 ± 34 | 0.845 ± 0.110 | 0.459 ± 0.055
Spleen | 506 ± 35 | 1.48 ± 0.19 | 0.0108 ± 0.0014
Stomach^d^ | NA | NA | 0.0636 ± 0.0072
Testis | 139 ± 7 | 0.404 ± 0.039 | 0.0158 ± 0.0010
Carcass^e^ | NA | NA | 0.485 ± 0.093

NA = Not applicable.

^a^ Data are presented as mean ± standard deviation for five rats.

^b^ Percent dose was calculated using the following values for the mass of total tissue expressed as percent of body weight: adipose, 7.0%; blood, 5.2%; muscle, 48.0%; and skin, 17% (taken from Donaldson^67^; Adolph^68^; Supplee et al.^69^; Caster et al.^70^; Bischoff et al.^71^; and Lutz et al.^72^).

^c^ Adipose and muscle values are averaged results for two sampling locations.

^d^ Includes contents.

^e^ Carcass value is based on the residual digested carcass after the removal of the listed tissues (i.e., percent dose measured in adipose, blood, muscle, and skin was subtracted from the total percent dose measured in the carcass).

Table J-3 Disposition of Radioactivity in Male F344 Rats 72 Hours Following a Single Oral Gavage Dose of 0.1 mg/kg [^14^C]-o-Chloropyridine^a^

End of Collection Period (Hours) | Urine | Feces | Exhaled CO_2_ | Volatile Organics | Total
6 | 18.8 ± 3.0 | –^b^ | 4.93 ± 0.63 | 0.518 ± 0.058 | 24.3 ± 3.1
12 | 29.1 ± 0.9 | 3.06 ± 2.30 | 8.47 ± 0.84 | 0.564 ± 0.084 | 41.2 ± 3.3
24 | 34.8 ± 0.7 | 24.0 ± 3.5 | 9.53 ± 0.83 | 0.579 ± 0.089 | 68.9 ± 3.4
48 | 37.0 ± 0.8 | 27.2 ± 3.0 | 10.2 ± 0.9 | 0.587 ± 0.088 | 75.0 ± 3.1
72 | 38.3 ± 0.8^c^ | 28.0 ± 2.5 | 10.5 ± 0.9 | 0.595 ± 0.089 | 77.4 ± 2.6
Disposition Summary
Excreta | | | | | 77.4 ± 2.6
Residual Carcass^d^ | | | | | 0.624 ± 0.176
Tissues^e^ | | | | | 3.88 ± 0.24
Total Dose Recovered | | | | | 81.9 ± 2.6

^a^ Data are presented as cumulative percentage of the dose (mean ± standard deviation) for five rats.

^b^ No collection was scheduled for this time interval.

^c^ Includes cage rinse.

^d^ Percent dose recovered in the residual carcass less the percent dose measured as individual tissues: adipose, blood, muscle, and skin.

^e^ Percent dose recovered in the following tissues: adipose, bladder, blood, brain, heart, kidney, liver, lung, muscle, skin, spleen, and testis. Also included were cecum, large and small intestine, and stomach, all with contents.

Table J-4 Tissue Distribution of Radioactivity in Male F344 Rats 72 Hours Following a Single Oral Gavage Dose of 0.1 mg/kg [^14^C]-o-Chloropyridine^a^

Tissue | o-Chloropyridine Equivalents in Tissue (ng-Eq/g Tissue) | Tissue:Blood Ratio | Dose in Total Tissue (%)^b^
Adipose^c^ | 1.43 ± 0.44 | 0.382 ± 0.122 | 0.0867 ± 0.0253
Bladder | 7.69 ± 1.46 | 7.69 ± 1.46 | 0.00221 ± 0.00055
Blood | 3.76 ± 0.07 | Unity | 0.171 ± 0.007
Brain | 1.28 ± 0.07 | 0.341 ± 0.018 | 0.00854 ± 0.00076
Cecum^d^ | NA | NA | 0.153 ± 0.040
Heart | 4.69 ± 0.23 | 1.25 ± 0.069 | 0.0147 ± 0.0010
Intestine, Large^d^ | NA | NA | 0.0416 ± 0.0095
Intestine, Small^d^ | NA | NA | 0.125 ± 0.017
Kidney | 27.1 ± 3.03 | 7.22 ± 0.93 | 0.185 ± 0.013
Liver | 49.0 ± 4.8 | 13.0 ± 1.27 | 1.44 ± 0.06
Lung | 5.68 ± 0.276 | 1.51 ± 0.086 | 0.0214 ± 0.0034
Muscle^c^ | 2.58 ± 0.37 | 0.687 ± 0.109 | 1.08 ± 0.15
Skin, Ear | 3.16 ± 0.40 | 0.839 ± 0.105 | 0.468 ± 0.066
Spleen | 6.33 ± 0.33 | 1.68 ± 0.10 | 0.0118 ± 0.0001
Stomach^d^ | NA | NA | 0.0578 ± 0.0157
Testis | 1.64 ± 0.06 | 0.437 ± 0.015 | 0.0172 ± 0.0010
Carcass^e^ | NA | NA | 2.42 ± 0.07

NA = Not applicable.

^a^ Data are presented as mean ± standard deviation for five rats.

^b^ Percent dose was calculated using the following values for the mass of total tissue expressed as percent of body weight: adipose, 7.0%; blood, 5.2%; muscle, 48.0%; and skin, 17% (taken from Donaldson^67^; Adolph^68^; Supplee et al.^69^; Caster et al.^70^; Bischoff et al.^71^; and Lutz et al.^72^).

^c^ Adipose and muscle values are averaged results for two sampling locations.

^d^ Includes contents.

^e^ Carcass value is based on the residual digested carcass after the removal of the listed tissues (i.e., percent dose measured in adipose, blood, muscle, and skin was subtracted from the total percent dose measured in the carcass).

Table J-5 Excretion of Radioactivity in Bile in Male F344 Rats Following a Single Intraperitoneal Injection of 50 mg/kg [^14^C]-o-Chloropyridine^a^

End of Collection Period (hours) | Bile
0.5 | 1.99 ± 0.69
1.0 | 6.10 ± 2.59
1.5 | 9.86 ± 4.55
2.0 | 13.5 ± 5.7
2.5 | 16.6 ± 6.3
3.0 | 20.8 ± 7.9
3.5 | 23.6 ± 8.2
4.0 | 26.9 ± 8.7

^a^ Data are presented as cumulative percentage of the dose (mean ± standard deviation) for five rats.

Table J-6 Total Radioactive Equivalents in Blood Over Time in Male F344 Rats Following a Single Oral Gavage Dose of 10 mg/kg [^14^C]-o-Chloropyridine^a^

Time After Dosing (hours) | o-Chloropyridine Equivalents in Blood (ng-Eq/g Blood) | Dose in Total Blood (%)
0.083 | 2,062 ± 316 | 1.07 ± 0.16
0.25 | 3,376 ± 738 | 1.75 ± 0.38
0.50 | 3,807 ± 462 | 1.97 ± 0.24
1 | 3,278 ± 570 | 1.70 ± 0.29
1.5 | 2,687 ± 243 | 1.39 ± 0.12
2 | 2,192 ± 305 | 1.14 ± 0.16
3 | 1,573 ± 166 | 0.814 ± 0.086
4 | 1,224 ± 111 | 0.634 ± 0.057
5 | 1,153 ± 78 | 0.597 ± 0.040
6 | 1,092 ± 73 | 0.565 ± 0.038
12 | 917 ± 102 | 0.475 ± 0.053
24 | 724 ± 87 | 0.375 ± 0.045
48^b^ | 475 ± 58 | 0.246 ± 0.030
72^c^ | 353 ± 23 | 0.183 ± 0.012

^a^ Data are presented as mean ± standard deviation for six rats.

Table J-7 Concentration of o-Chloropyridine and Total Radioactive Equivalents in Blood Over Time in Male F344 Rats Following a Single Intravenous Injectionof 1 mg/kg [^14^C]-o-Chloropyridine^a^

Time After Dosing (Hours) | o-Chloropyridine (ng/g Blood) | Radiolabel o-Chloropyridine Equivalents (ng-Eq/g Blood) | Radiolabel Dose in Total Blood (%)
0.083 | 567 ± 23 | 632 ± 146 | 4.09 ± 0.99
0.17 | 437 ± 31 | 422 ± 39 | 2.76 ± 0.27
0.25 | 360 ± 31 | 356 ± 5 | 2.30 ± 0.06
0.50 | 220 ± 20 | 286 ± 35 | 1.85 ± 0.26
1 | 123 ± 10 | 209 ± 37 | 1.35 ± 0.24
1.5 | 100 ± 43 | 138 ± 11 | 0.893 ± 0.075
2 | 73.2 ± 53.4 | 100 ± 9 | 0.646 ± 0.069
3 | ND | 74.9 ± 6.1 | 0.484 ± 0.041
4 | ND | 74.9 ± 4.8 | 0.483 ± 0.025

ND = Not determined.

^a^ Data are presented as mean ± standard deviation for four rats.

Figure J-1

[^14^C]-Labeled Urinary Metabolites in Male F344 Rats Following a Single Oral Gavage Dose of 10 mg/kg [^14^C]-o-Chloropyridine

Metabolites were determined in a composite (0 to 24 hours) urine sample from one rat.

Figure J-2

Disubstituted Urinary Metabolites of o-Chloropyridine in Male F344 Rats

Figure J-3

Blood Timecourse and Toxicokinetic Parameter Estimates of o-Chloropyridine in Male F344 Rats Following a Single Oral Gavage Dose of 10 mg/kg [^14^C]-o-Chloropyridine

Data were fitted using a two-compartment model. Constants A and B are intercepts on the y axis for each exponential segment of the curve and β and α are the elimination and distribution rate constants, respectively.

Figure J-4

Blood Timecourse and Toxicokinetic Parameter Estimates for o-Chloropyridine and Radiolabel (o-Chloropyridine Equivalents) in Blood of Male F344 Rats Following a Single Intravenous Injection of 1 mg/kg [^14^C]-o-Chloropyridine