# Appendix G Water and Compound Consumption in the Three-month Drinking Water Studies of o-Chloropyridine

Table G-1 Water and Compound Consumption by Male Rats in the Three-month Drinking Water Study of o-Chloropyridine

Week | 0 ppm | | 10 ppm | | | 30 ppm | | | 100 ppm
Week | Water^a^ (g/day) | Body Weight (g) | Water (g/day) | Body Weight (g) | Dose^b^ (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg)
1 | 14.7 | 90 | 15.5 | 93 | 1.7 | 15.1 | 92 | 4.9 | 15.4 | 91 | 16.9
2 | 14.9 | 119 | 16.6 | 123 | 1.3 | 15.8 | 123 | 3.8 | 15.4 | 120 | 12.9
3 | 16.6 | 146 | 17.7 | 152 | 1.2 | 18.3 | 152 | 3.6 | 15.7 | 148 | 10.6
4 | 17.2 | 175 | 18.3 | 182 | 1.0 | 18.8 | 184 | 3.1 | 16.6 | 174 | 9.6
5 | 17.3 | 199 | 17.6 | 205 | 0.9 | 18.4 | 209 | 2.6 | 18.8 | 195 | 9.6
6 | 15.7 | 217 | 16.6 | 225 | 0.7 | 17.2 | 230 | 2.2 | 20.2 | 213 | 9.5
7 | 16.5 | 234 | 19.3 | 239 | 0.8 | 18.9 | 247 | 2.3 | 16.8 | 233 | 7.2
8 | 16.2 | 247 | 17.1 | 254 | 0.7 | 21.7 | 263 | 2.5 | 17.1 | 247 | 6.9
9 | 16.4 | 262 | 16.5 | 268 | 0.6 | 18.0 | 278 | 1.9 | 18.0 | 260 | 6.9
10 | 16.0 | 275 | 15.9 | 281 | 0.6 | 19.0 | 295 | 1.9 | 19.5 | 277 | 7.0
11 | 16.3 | 285 | 16.0 | 291 | 0.6 | 17.3 | 305 | 1.7 | 19.7 | 289 | 6.8
12 | 16.9 | 297 | 17.0 | 302 | 0.6 | 17.3 | 316 | 1.6 | 19.6 | 305 | 6.4
13 | 16.8 | 306 | 16.2 | 311 | 0.5 | 18.8 | 324 | 1.7 | 18.1 | 312 | 5.8
14 | 17.3 | 320 | 17.7 | 326 | 0.5 | 13.6 | 326 | 1.3 | 18.1 | 326 | 5.6
| | | | | | 300 ppm | | | 1,000 ppm
| | | | | | Water (g/day) | Body Weight (g) | Dose (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg)
1 | | | | | | 13.6 | 91 | 44.9 | 6.5 | 94 | 68.9
2 | | | | | | 15.2 | 118 | 38.6 | 8.8 | 98 | 89.6
3 | | | | | | 16.6 | 145 | 34.3 | 10.2 | 121 | 84.5
4 | | | | | | 16.9 | 172 | 29.5 | 11.3 | 145 | 77.9
5 | | | | | | 16.5 | 192 | 25.8 | 12.0 | 164 | 73.0
6 | | | | | | 15.2 | 210 | 21.7 | 11.3 | 182 | 62.1
7 | | | | | | 17.7 | 222 | 24.0 | 11.7 | 195 | 60.0
8 | | | | | | 16.9 | 239 | 21.2 | 11.6 | 209 | 55.4
9 | | | | | | 16.0 | 255 | 18.9 | 12.8 | 222 | 57.7
10 | | | | | | 15.8 | 267 | 17.8 | 13.0 | 219 | 59.4
11 | | | | | | 16.1 | 275 | 17.6 | 12.7 | 235 | 54.0
12 | | | | | | 16.4 | 286 | 17.2 | 12.8 | 249 | 51.4
13 | | | | | | 16.1 | 293 | 16.5 | 13.0 | 258 | 50.4
14 | | | | | | 17.5 | 309 | 17.0 | 15.1 | 268 | 56.4

^a^ Grams of water consumed per animal per day.

^b^ Milligrams of o-chloropyridine consumed per kilogram body weight per day.

Table G-2 Water and Compound Consumption by Female Rats in the Three-month Drinking Water Study of o-Chloropyridine

Week | 0 ppm | | 10 ppm | | | 30 ppm | | | 100 ppm
Week | Water^a^ (g/day) | Body Weight (g) | Water (g/day) | Body Weight (g) | Dose^b^ (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg)
1 | 12.5 | 86 | 13.8 | 88 | 1.6 | 13.0 | 87 | 4.5 | 12.6 | 88 | 14.3
2 | 13.4 | 106 | 13.8 | 108 | 1.3 | 13.6 | 108 | 3.8 | 13.4 | 108 | 12.5
3 | 13.9 | 120 | 14.1 | 122 | 1.2 | 15.8 | 123 | 3.8 | 13.5 | 122 | 11.1
4 | 14.4 | 135 | 14.8 | 137 | 1.1 | 15.5 | 139 | 3.3 | 13.8 | 137 | 10.1
5 | 15.5 | 146 | 15.7 | 149 | 1.1 | 15.7 | 150 | 3.1 | 12.4 | 149 | 8.3
6 | 14.0 | 158 | 15.7 | 161 | 1.0 | 14.9 | 160 | 2.8 | 15.2 | 161 | 9.5
7 | 14.0 | 168 | 14.4 | 171 | 0.8 | 16.2 | 169 | 2.9 | 13.8 | 170 | 8.1
8 | 13.5 | 175 | 14.0 | 177 | 0.8 | 16.3 | 176 | 2.8 | 13.3 | 176 | 7.6
9 | 12.4 | 179 | 13.4 | 181 | 0.7 | 13.8 | 180 | 2.3 | 12.9 | 179 | 7.2
10 | 13.0 | 184 | 13.6 | 185 | 0.7 | 14.4 | 185 | 2.3 | 12.7 | 183 | 6.9
11 | 14.3 | 188 | 13.5 | 190 | 0.7 | 14.6 | 190 | 2.3 | 14.5 | 189 | 7.7
12 | 14.2 | 191 | 13.9 | 194 | 0.7 | 14.1 | 195 | 2.2 | 14.5 | 192 | 7.6
13 | 14.1 | 192 | 13.8 | 196 | 0.7 | 15.2 | 195 | 2.3 | 12.8 | 194 | 6.6
14 | 13.4 | 195 | 17.7 | 200 | 0.9 | 14.8 | 200 | 2.2 | 17.4 | 196 | 8.9
| | | | | | 300 ppm | | | 1,000 ppm
| | | | | | Water (g/day) | Body Weight (g) | Dose (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg)
1 | | | | | | 12.2 | 86 | 42.6 | 6.1 | 87 | 70.1
2 | | | | | | 13.1 | 105 | 37.6 | 7.7 | 89 | 86.1
3 | | | | | | 13.3 | 119 | 33.7 | 8.7 | 105 | 83.1
4 | | | | | | 13.6 | 132 | 30.9 | 9.4 | 119 | 78.9
5 | | | | | | 13.7 | 145 | 28.4 | 10.0 | 130 | 77.0
6 | | | | | | 13.1 | 155 | 25.4 | 10.0 | 139 | 71.9
7 | | | | | | 12.7 | 163 | 23.4 | 9.8 | 148 | 66.4
8 | | | | | | 12.8 | 168 | 22.8 | 9.8 | 154 | 63.7
9 | | | | | | 12.2 | 173 | 21.2 | 9.8 | 158 | 62.0
10 | | | | | | 12.6 | 176 | 21.5 | 10.1 | 163 | 61.9
11 | | | | | | 12.2 | 182 | 20.1 | 10.3 | 167 | 61.6
12 | | | | | | 12.3 | 185 | 20.0 | 10.5 | 170 | 61.6
13 | | | | | | 13.0 | 187 | 20.8 | 10.4 | 173 | 60.2
14 | | | | | | 12.7 | 190 | 20.0 | 15.8 | 174 | 90.9

^a^ Grams of water consumed per animal per day.

^b^ Milligrams of o-chloropyridine consumed per kilogram body weight per day.

Table G-3 Water and Compound Consumption by Male Mice in the Three-month Drinking Water Study of o-Chloropyridine

Week | 0 ppm | | 10 ppm | | | 30 ppm | | | 100 ppm
Week | Water^a^ (g/day) | Body Weight (g) | Water (g/day) | Body Weight (g) | Doseb (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg)
1 | 4.8 | 23.2 | 5.1 | 23.2 | 2.2 | 5.4 | 23.3 | 7.0 | 5.3 | 23.3 | 22.7
2 | 4.9 | 25.9 | 5.2 | 26.2 | 2.0 | 5.4 | 26.2 | 6.2 | 5.1 | 26.0 | 19.6
3 | 4.6 | 27.5 | 4.8 | 27.6 | 1.7 | 5.0 | 28.1 | 5.3 | 4.5 | 27.7 | 16.2
4 | 4.5 | 29.0 | 4.8 | 29.4 | 1.6 | 4.5 | 29.9 | 4.5 | 4.5 | 29.4 | 15.3
5 | 4.9 | 30.5 | 5.1 | 31.1 | 1.6 | 5.0 | 31.6 | 4.7 | 4.7 | 30.9 | 15.2
6 | 4.3 | 31.9 | 4.6 | 32.9 | 1.4 | 4.7 | 33.3 | 4.2 | 4.8 | 32.1 | 15.0
7 | 4.8 | 33.9 | 4.8 | 34.4 | 1.4 | 4.9 | 34.8 | 4.2 | 4.5 | 33.4 | 13.5
8 | 5.1 | 35.4 | 5.1 | 36.2 | 1.4 | 4.9 | 36.4 | 4.0 | 5.1 | 34.8 | 14.7
9 | 4.1 | 36.5 | 4.8 | 37.4 | 1.3 | 4.8 | 37.6 | 3.8 | 4.8 | 36.1 | 13.3
10 | 4.6 | 37.5 | 4.5 | 38.4 | 1.2 | 4.6 | 38.6 | 3.6 | 4.5 | 37.1 | 12.1
11 | 4.7 | 37.5 | 4.8 | 38.9 | 1.2 | 4.4 | 38.7 | 3.4 | 4.5 | 37.5 | 12.0
12 | 5.0 | 38.8 | 5.1 | 40.3 | 1.3 | 4.9 | 40.1 | 3.7 | 5.0 | 38.2 | 13.1
13 | 5.1 | 40.1 | 5.2 | 41.7 | 1.2 | 5.2 | 41.2 | 3.8 | 4.8 | 39.3 | 12.2
14 | 4.5 | 40.8 | 4.6 | 42.4 | 1.1 | 4.9 | 42.4 | 3.5 | 5.4 | 40.2 | 13.4
| | | | | | 300 ppm | | | 1,000 ppm
| | | | | | Water (g/day) | Body Weight (g) | Dose (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg)
1 | | | | | | 4.4 | 23.1 | 57.1 | 3.2 | 23.1 | 138.3
2 | | | | | | 4.5 | 25.9 | 52.1 | 2.8 | 24.6 | 113.8
3 | | | | | | 4.4 | 27.8 | 47.4 | 3.0 | 26.0 | 115.4
4 | | | | | | 4.3 | 29.4 | 43.9 | 2.9 | 26.8 | 108.4
5 | | | | | | 4.4 | 30.8 | 42.8 | 3.2 | 27.7 | 115.5
6 | | | | | | 4.2 | 32.5 | 38.8 | 3.2 | 28.8 | 111.3
7 | | | | | | 4.2 | 34.0 | 37.1 | 3.3 | 29.7 | 111.1
8 | | | | | | 4.7 | 35.6 | 39.6 | 3.4 | 30.5 | 111.6
9 | | | | | | 4.3 | 36.9 | 34.9 | 3.3 | 31.0 | 106.6
10 | | | | | | 4.2 | 37.7 | 33.4 | 3.2 | 31.4 | 101.9
11 | | | | | | 4.1 | 37.8 | 32.5 | 3.0 | 31.5 | 95.4
12 | | | | | | 4.3 | 38.7 | 33.3 | 3.3 | 32.0 | 103.0
13 | | | | | | 4.9 | 40.0 | 36.7 | 3.4 | 32.5 | 104.6
14 | | | | | | 4.7 | 40.5 | 34.8 | 3.3 | 33.0 | 100.1

^a^ Grams of water consumed per animal per day.

^b^ Milligrams of o-chloropyridine consumed per kilogram body weight per day.

Table G-4 Water and Compound Consumption by Female Mice in the Three-month Drinking Water Study of o-Chloropyridine

Week | 0 ppm | | 10 ppm | | | 30 ppm | | | 100 ppm
Week | Water^a^ (g/day) | Body Weight (g) | Water (g/day) | Body Weight (g) | Dose^b^ (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg)
1 | 2.8 | 18.6 | 3.0 | 19.1 | 1.6 | 2.7 | 18.8 | 4.3 | 2.3 | 19.0 | 12.1
2 | 3.1 | 19.9 | 2.9 | 20.6 | 1.4 | 2.9 | 20.0 | 4.3 | 2.7 | 19.7 | 13.7
3 | 2.9 | 19.7 | 2.5 | 20.6 | 1.2 | 3.0 | 20.6 | 4.4 | 2.9 | 20.3 | 14.3
4 | 3.3 | 21.4 | 2.6 | 19.5 | 1.3 | 2.5 | 21.4 | 3.5 | 2.8 | 21.5 | 13.0
5 | 3.7 | 23.3 | 3.7 | 23.1 | 1.6 | 3.4 | 22.6 | 4.5 | 3.0 | 22.8 | 13.1
6 | 3.0 | 23.2 | 3.1 | 23.3 | 1.3 | 3.0 | 23.8 | 3.8 | 2.5 | 23.0 | 10.9
7 | 3.1 | 25.2 | 3.5 | 25.4 | 1.4 | 3.1 | 25.5 | 3.7 | 3.1 | 25.4 | 12.2
8 | 2.8 | 25.6 | 3.1 | 26.5 | 1.2 | 2.8 | 26.1 | 3.2 | 2.5 | 26.3 | 9.5
9 | 3.3 | 27.4 | 3.4 | 27.0 | 1.3 | 3.4 | 26.3 | 3.9 | 3.0 | 27.3 | 11.0
10 | 3.1 | 27.0 | 3.2 | 27.7 | 1.2 | 3.3 | 27.7 | 3.6 | 3.1 | 27.8 | 11.1
11 | 3.0 | 28.3 | 3.3 | 28.6 | 1.2 | 3.1 | 28.5 | 3.3 | 3.1 | 28.6 | 10.9
12 | 3.7 | 29.3 | 3.7 | 29.2 | 1.3 | 3.2 | 29.5 | 3.3 | 3.1 | 29.7 | 10.4
13 | 3.0 | 29.2 | 4.3 | 30.1 | 1.4 | 2.4 | 30.6 | 2.4 | 2.6 | 29.6 | 8.8
14 | 3.5 | 28.5 | 3.3 | 31.8 | 1.0 | 3.4 | 31.2 | 3.3 | 3.4 | 30.3 | 11.2
| | | | | | 300 ppm | | | 1,000 ppm
| | | | | | Water (g/day) | Body Weight (g) | Dose (mg/kg) | Water (g/day) | Body Weight (g) | Dose (mg/kg)
1 | | | | | | 3.3 | 18.1 | 54.7 | 1.6 | 18.5 | 86.3
2 | | | | | | 2.7 | 20.3 | 40.0 | 3.8 | 18.9 | 200.3
3 | | | | | | 3.3 | 22.1 | 44.7 | 1.4 | 18.9 | 74.0
4 | | | | | | 2.6 | 22.3 | 34.9 | 1.1 | 21.0 | 52.4
5 | | | | | | 3.7 | 23.9 | 46.4 | 1.3 | 23.0 | 56.5
6 | | | | | | 2.9 | 25.0 | 34.8 | 2.4 | 22.9 | 104.7
7 | | | | | | 2.9 | 26.4 | 33.0 | 2.1 | 24.7 | 85.1
8 | | | | | | 2.7 | 26.6 | 30.5 | 2.2 | 25.2 | 87.3
9 | | | | | | 3.2 | 28.4 | 33.8 | 2.3 | 25.8 | 89.3
10 | | | | | | 3.3 | 29.3 | 33.8 | 2.6 | 26.8 | 96.9
11 | | | | | | 4.3 | 30.0 | 43.0 | 2.5 | 27.5 | 91.0
12 | | | | | | 3.4 | 31.3 | 32.6 | 2.9 | 28.3 | 102.6
13 | | | | | | 3.2 | 31.2 | 30.8 | 1.8 | 27.6 | 65.2
14 | | | | | | 3.4 | 31.9 | 32.0 | 2.8 | 28.4 | 98.6

^a^ Grams of water consumed per animal per day.

^b^ Milligrams of o-chloropyridine consumed per kilogram body weight per day.