# Appendix F Chemical Characterization and Dose Formulation Studies

## F. 1 Procurement and Characterization

### F.1.1 o-Chloropyridine

o-Chloropyridine was obtained from Aldrich Chemical Company (Milwaukee, WI) in one lot (15306CN) that was used in the 2-week dermal and 3-month drinking water studies. Identity and purity analyses were conducted by the analytical chemistry laboratory at Battelle (Columbus, OH, and Richland, WA), Chemir/Polytech Laboratories, Inc. (Maryland Heights, MO), Galbraith Laboratories, Inc. (Knoxville, TN), and the study laboratory, BioReliance Corporation (Rockville, MD). Reports on analyses performed in support of the o-chloropyridine studies are on file at the National Institute of Environmental Health Sciences.

The chemical, a clear colorless liquid, was identified as o-chloropyridine by the analytical chemistry laboratory, Chemir/Polytech Laboratories, Inc., and the study laboratory using infrared (IR) spectroscopy and by the analytical chemistry laboratory and Chemir/Polytech Laboratories, Inc., using proton and carbon-13 nuclear magnetic resonance (NMR) spectroscopy. All spectra were consistent with the literature spectra^55,56^ of o-chloropyridine. The IR and NMR spectra are presented in Figure F-1, Figure F-2, and Figure F-3.

The purity of lot 15306CN was determined by Galbraith Laboratories, Inc., using elemental analyses and by the analytical chemistry laboratory using gas chromatography (GC). Elemental analyses for carbon, hydrogen, nitrogen, and chlorine were in agreement with the theoretical values for o-chloropyridine. GC using system A (Table F-1) indicated one major peak and two impurities with areas at least 0.1% relative to the major peak area; the purity of the bulk chemical was determined to be greater than 99%. GC using system B indicated one major peak and two impurity peaks with areas at least 0.1% of the major peak area; the purity of the test chemical was determined to be greater than 99.5%. The overall purity of lot 15306CN was determined to be 99% or greater.

To ensure stability, the bulk chemical was stored at room temperature in sealed amber glass bottles under a headspace of inert gas, protected from light and moisture. Periodic reanalyses of the bulk chemical were performed during the 2-week and 3-month studies by the study laboratory using GC by system C, and no degradation of the bulk chemical was detected.

### F.1.2 Ethanol

Ninety-five percent ethanol was obtained from Clear Spring Distilling Company (Clermont, KY) in one lot (21049312) that was used as the dosing vehicle in the 2-week dermal studies. Lot 21049312, a clear liquid, was identified as ethanol by the study laboratory using IR spectroscopy; the IR spectrum was consistent with a literature spectrum^57^ of ethanol.

The purity of lot 21049312 was determined by the study laboratory using GC by system D (Table F-1). Analysis indicated one major peak and three impurities each with a relative concentration of less than or equal to 0.0001%.

## F.2 Preparation and Analysis of Dose Formulations

### F.2.1 Dermal Studies

The dose formulations were prepared once during the 2-week studies by mixing o-chloropyridine with 95% ethanol to give the required concentrations (Table F-2). The dose formulations were stored under a headspace of inert gas in refrigerated amber glass vials with Teflon^®^-lined lids for up to 23 days.

Stability studies of a 3.125 mg/mL dose formulation were performed by the analytical chemistry laboratory with GC by system E (Table F-1). Stability was confirmed for at least 43 days for dose formulations stored in sealed amber glass vials at room temperature, 5°C, or −20°C. Data from a simulated animal room stability study indicated that o-chloropyridine was stable dissolved in 95% ethanol when exposed to light for up to 3 hours at room temperature.

The dose formulations were analyzed on the day they were prepared by the study laboratory using GC by system C. All seven dose formulations analyzed for rats and mice were within 10% of the target concentrations (Table F-3). Animal room samples of these dose formulations were also analyzed; one of five formulations for rats and all five formulations for mice were within 10% of the target concentrations. High concentrations measured for some of the rat animal room samples were attributed to improper sealing of the vials after dosing and possible solvent evaporation.

### F.2.2 Drinking Water Studies

The dose formulations were prepared nine times during the 3-month studies by mixing o-chloropyridine with tap water to give the required concentrations (Table F-2). The dose formulations were stored refrigerated in Cubitainers^®^ with taps, protected from light, for up to 21 days.

Because all dose formulations in these studies were determined to be solutions, no homogeneity studies were required. Stability studies of the 10 ppm dose formulation were performed by the analytical chemistry laboratory with high-performance liquid chromatography (HPLC). The analytical system consisted of a Waters (Waters Corporation, Milford, MA) or Spectra-Physics (Spectra-Physics, Inc., Mountain View, CA) liquid chromatograph, a Luna^®^ (5 µm particle size, C18 150 mm × 4.6 mm) column (Phenomenex, Inc., Torrance, CA), an isocratic mobile phase of acetonitrile:Milli-Q^®^ water:glacial acetic acid (33:66:1) at a flow rate of 1.0 mL/minute, and ultraviolet detection at 254 nm. Stability was confirmed for at least 43 days for dose formulations stored in sealed polyethylene bottles protected from light at 5°C and for at least 8 days under simulated animal room conditions.

The dose formulations were analyzed at the beginning, midpoint, and end of the studies by the study laboratory using the HPLC system described above for the dose formulation stability studies; animal room samples of these dose formulations were also analyzed. All 15 dose formulations analyzed and used for rats and mice were within 10% of the target concentrations (Table F-4). Of the animal room samples analyzed, all 15 for rats and 12 of 15 for mice were within 10% of the target concentrations, and the remaining three were less than 12% of the target concentrations.

Table F-1 Gas Chromatography Systems Used in the Studies of o-Chloropyridine^a^

Detection System | Column | Oven Temperature Program
System A
Flame ionization | Stabilwax^®^, 30 m × 0.53 mm, 1.0 µm film (Restek, Bellefonte, PA) | 65°C for 1 minute, then 5°C/minute to 230°C, held for 1 minute
System B
Flame ionization | Stabilwax^®^-DB, 30 m × 0.25 mm, 0.5 µm film (Restek) | 50°C for 1 minute, then 10°C/minute to 200°C, held for 13 minutes
System C
Flame ionization | DB^TM^-WAX, 30 m × 0.53 mm, 1.0 µm film (J&W Scientific, Folsom, CA) | 75°C for 1 minute, then 7°C/minute to 180°C, then 15°C/minute to 230°C, held for 1 minute
System D
Flame ionization | DB^TM^-WAX, 30 m × 0.53 mm, 1.0 µm film, J&W Scientific | 40°C for 5 minutes, then 10°C/minute to 220°C, held for 5 minutes
System E
Flame ionization | Stabilwax^®^-DB, 30 m × 0.25 mm, 0.5 µm film (Restek) | 75°C for 1 minute, then 7°C/minute to 180°C, then 15°C/minute to 230°C, held for 1 minute

^a^ All gas chromatographs were manufactured by Hewlett-Packard, (Palo Alto, CA).

Table F-2 Preparation and Storage of Dose Formulations in the Studies of o-Chloropyridine

Two-week Dermal Studies | Three-month Drinking Water Studies
Preparation
Each dose formulation was prepared by diluting a weighed amount of o-chloropyridine with a specified volume of 95% ethanol in a graduated cylinder. The dose formulations were stirred on a magnetic stirrer until the mixtures were homogenized. Dose formulations were prepared once during the studies. | Tap water was weighed to a volume of 1 L less than the final volume of the formulation into a Cubitainer^®^. Water was removed from the Cubitainer^®^ to account for the volume of o-chloropyridine to be added. o-Chloropyridine was weighed into a tared glass beaker and the contents were quantitatively transferred to the Cubitainer^®^ using 1 L of tap water measured in a beaker. The final mixture was agitated by vigorous shaking. Dose formulations were prepared nine times.
Chemical Lot Number
15306CN | 15306CN
Maximum Storage Time
23 days | 21 days
Storage Conditions
The dose formulations were stored in amber glass vials under a headspace of inert gas; the vials were sealed with Teflon^®^-lined septa and crimped aluminum caps and were stored refrigerated. | Dose formulations were stored in 20 L Cubitainers^®^ with taps, refrigerated and protected from light.
Study Laboratory
BioReliance Corporation (Rockville, MD) | BioReliance Corporation (Rockville, MD)

Table F-3 Results of Analyses of Dose Formulations Administered to Rats and Mice in the Two-week Dermal Studies of o-Chloropyridine

Date Prepared | Date Analyzed | Target Concentration^a^ (mg/mL) | Determined Concentration^b^ (mg/mL) | Difference from Target (%)
September 12, 2000 | September 12, 2000 | 3.13 | 3.20 | +7
| | 6.25 | 6.31 | +1
| | 12.5 | 12.4 | −1
| | 25 | 25.1 | 0
| | 50 | 49.0 | −2
| | 100 | 98.0 | −2
| | 200 | 194 | −3
| October 11, 2000^c^ | 12.5 | 13.5 | +8
| | 25 | 29.2 | +17
| | 50 | 55.3 | +11
| | 100 | 111 | +11
| | 200 | 236 | +18
| October 11, 2000^d^ | 3.13 | 3.22 | +3
| | 6.25 | 6.38 | +2
| | 12.5 | 12.9 | +3
| | 25 | 26.5 | +6
| | 50 | 53.1 | +6

^a^ The 3.13 and 6.25 mg/mL dose formulations were used only for mice, and the 100 and 200 mg/mL dose formulations were used only for rats.

^b^ Results of duplicate analyses. For rats, dosing volume = 0.5 mL/kg; 12.5 mg/mL = 6.25 mg/kg, 25 mg/mL = 12.5 mg/kg, 50 mg/mL = 25 mg/kg; 100 mg/mL = 50 mg/kg; 200 mg/mL = 100 mg/kg. For mice, dosing volume = 2 mL/kg; 3.13 mg/mL = 6.25 mg/kg, 6.25 mg/mL = 12.5 mg/kg, 12.5 mg/mL = 25 mg/kg; 25 mg/mL = 50 mg/kg, 50 mg/mL = 100 mg/kg.

^c^ Animal room samples for rats.

^d^ Animal room samples for mice.

Table F-4 Results of Analyses of Dose Formulations Administered to Rats and Mice in the Three-month Drinking Water Studies of o-Chloropyridine

Date Prepared | Date Analyzed | Target Concentration (ppm) | Determined Concentration^a^ (ppm) | Difference from Target (%)
July 22, 2003 | July 22, 2003 | 10 | 9.76 | −2
| | 30 | 29.7 | −1
| | 100 | 97.9 | −2
| | 300 | 300 | 0
| | 1,000 | 897^b^ | −10
| August 7, 2003^c^ | 10 | 9.23 | −8
| | 30 | 27.9 | −7
| | 100 | 94.2 | −6
| | 300 | 278 | −7
| August 7, 2003^d^ | 10 | 8.79 | −12
| | 30 | 26.7 | −11
| | 100 | 93.0 | −7
| | 300 | 270 | −10
July 25, 2003 | July 25, 2003 | 1,000 | 982^e^ | −2
| August 7, 2003^c^ | 1,000 | 936 | −6
| August 7, 2003^d^ | 1,000 | 905 | −10
August 25, 2003 | August 26, 2003 | 10 | 9.92 | −1
| | 30 | 28.8 | −4
| | 100 | 98.1 | −2
| | 300 | 296 | −1
| | 1,000 | 992 | −1
| September 17, 2003^c^ | 10 | 9.33 | −7
| | 30 | 28.0 | −7
| | 100 | 92.0 | −8
| | 300 | 282 | −6
| | 1,000 | 944 | −6
| September 17, 2003^d^ | 10 | 9.16 | −8
| | 30 | 27.1 | −10
| | 100 | 92.1 | −8
| | 300 | 279 | −7
| | 1,000 | 889 | −11
October 14, 2003 | October 16, 2003 | 10 | 9.54 | −5
| | 30 | 28.8 | −4
| | 100 | 98.0 | −2
| | 300 | 290 | −3
| | 1,000 | 974 | −3
| November 5, 2003^c^ | 10 | 9.59 | −4
| | 30 | 28.3 | −6
| | 100 | 94.6 | −5
| | 300 | 278 | −7
| | 1,000 | 930 | −7
| November 5, 2003^d^ | 10 | 9.31 | −7
| | 30 | 28.0 | −7
| | 100 | 95.1 | −5
| | 300 | 269 | −10
| | 1,000 | 914 | −9

^a^ Results of duplicate analyses.

^b^ Remixed; not used in studies.

^c^ Animal room samples for rats.

^d^ Animal room samples for mice.

^e^ Results of remix.

Figure F-1

Infrared Absorption Spectrum of o-Chloropyridine

Figure F-2

Proton Nuclear Magnetic Resonance Spectrum of o-Chloropyridine

Figure F-3

Carbon-13 Nuclear Magnetic Resonance Spectrum of o-Chloropyridine