# Appendix E Genetic Toxicology

Table E-1 Mutagenicity of o-Chloropyridine in Salmonella typhimurium^a^

Strain | Dose (μg/plate) | Without S9 | With 30% Hamster S9 | With 30% Hamster S9 | With 30% Rat S9 | With 30% Rat S9
TA100 | 0 | 116 ± 6 | 111 ± 9 | 127 ± 6 | 151 ± 4 | 128 ± 6
| 10 | | | 127 ± 1
| 33 | | | 155 ± 13
| 100 | 130 ± 2 | 220 ± 8 | 231 ± 18 | 153 ± 7
| 166 | | | 362 ± 13
| 333 | 137 ± 4 | 461 ± 32 | 496 ± 18 | 168 ± 10 | 159 ± 6
| 666 | | | | | 180 ± 8
| 1,000 | 114 ± 9 | 1,254 ± 8 | | 294 ± 4 | 251 ± 19
| 1,666 | | | | | 358 ± 17
| 3,333 | 126 ± 5 | 1,146 ± 24 | | 557 ± 21 | 554 ± 20
| 6,666 | 117 ± 1
| 10,000 | | Toxic | | 157 ± 14^b^
Trial summary | | Negative | Positive | Positive | Positive | Positive
Positive control^c^ | | 850 ± 20 | 645 ± 18 | 661 ± 19 | 541 ± 19 | 626 ± 13
TA98 | 0 | 22 ± 2 | 21 ± 2 | 24 ± 3 | 16 ± 3 | 22 ± 2
| 100 | 20 ± 1 | 27 ± 1 | 30 ± 1 | 21 ± 4
| 166 | | | 45 ± 2
| 333 | 19 ± 3 | 57 ± 7 | 71 ± 2 | 19 ± 3 | 25 ± 2
| 666 | | | 106 ± 4 | | 34 ± 3
| 1,000 | 22 ± 1 | 256 ± 6 | 251 ± 20 | 43 ± 3 | 48 ± 2
| 1,666 | | | | | 52 ± 1
| 3,333 | 21 ± 4 | 286 ± 4 | | 68 ± 3 | 64 ± 3
| 6,666 | 17 ± 1
| 10,000 | | Toxic | | 6 ± 1^d^
Trial summary | | Negative | Positive | Positive | Positive | Positive
Positive control | | 421 ± 28 | 311 ± 6 | 457 ± 15 | 251 ± 13 | 410 ± 6

^a^ Study was performed at SRI International. The detailed protocol is presented by Zeiger et al.^47^ Data are presented as revertants/plate (mean ± standard error) from three plates. 0 μg/plate was the solvent control.

^b^ Slight toxicity.

^c^ The positive controls in the absence of metabolic activation were sodium azide (TA100) and 4-nitro-o-phenylenediamine (TA98). The positive control for metabolic activation with both strains was 2-aminoanthracene.

^d^ Slight toxicity and precipitate on plate.

Table E-2 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Mice Following Administration of o-Chloropyridine in Drinking Water for Three Months^a^

| Exposure Concentration (ppm) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs^b^ (%)
Male
Water^d^ | 0 | 5 | 4.00 ± 0.35 | | 3.92 ± 0.35
o-Chloropyridine | 10 | 5 | 3.90 ± 0.60 | 0.5449 | 4.34 ± 0.55
| 30 | 5 | 3.80 ± 0.37 | 0.5897 | 3.66 ± 0.46
| 100 | 5 | 3.10 ± 0.33 | 0.8577 | 3.20 ± 0.28
| 300 | 5 | 2.70 ± 0.41 | 0.9442 | 3.56 ± 0.19
| 1,000 | 5 | 2.70 ± 0.20 | 0.9442 | 3.80 ± 0.22
| | | P = 0.959^e^
Female
Water | 0 | 5 | 2.40 ± 0.24 | | 3.52 ± 0.57
o-Chloropyridine | 10 | 5 | 1.60 ± 0.29 | 0.8973 | 3.72 ± 0.23
| 30 | 5 | 2.90 ± 0.64 | 0.2458 | 4.54 ± 0.39
| 100 | 5 | 1.50 ± 0.32 | 0.9254 | 3.94 ± 0.53
| 300 | 5 | 2.60 ± 0.29 | 0.3885 | 3.88 ± 0.56
| 1,000 | 5 | 2.10 ± 0.48 | 0.6728 | 3.50 ± 0.24
| | | P = 0.511

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by MacGregor et al.^48^ NCE = normochromatic erythrocyte; PCE = polychromatic erythrocyte.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the untreated control group; exposed group values are significant at P ≤ 0.005.

^d^ Untreated control.

^e^ Significance of micronucleated NCEs/1,000 NCEs tested by the one-tailed trend test; significant at P ≤ 0.025.