# Appendix D Reproductive Tissue Evaluations and Estrous Cycle Characterization

Table D-1 Summary of Reproductive Tissue Evaluations for Male Rats in the Three-month Drinking Water Study of o-Chloropyridine^a^

| 0 ppm | 100 ppm | 300 ppm | 1,000 ppm
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 320 ± 6 | 326 ± 8 | 309 ± 7 | 268 ± 6**
L. Cauda epididymis | 0.1510 ± 0.0067 | 0.1563 ± 0.0040 | 0.1548 ± 0.0041 | 0.1503 ± 0.0037
L. Epididymis | 0.4239 ± 0.0177 | 0.4579 ± 0.0097 | 0.4457 ± 0.0063 | 0.4222 ± 0.0079
L. Testis | 1.4547 ± 0.0387 | 1.5359 ± 0.0227 | 1.4795 ± 0.0269 | 1.4671 ± 0.0212
Spermatid measurements
Spermatid heads (10^6^/testis) | 169.75 ± 7.20 | 182.13 ± 5.88 | 170.88 ± 4.14 | 166.75 ± 4.25
Spermatid heads (10^6^/g testis) | 129.7 ± 3.6 | 131.9 ± 4.6 | 126.8 ± 2.8 | 125.6 ± 3.0
Epididymal spermatozoal measurements
Sperm motility (%) | 77.6 ± 1.0 | 71.7 ± 8.0 | 76.9 ± 1.4 | 77.4 ± 1.0
Sperm (10^6^/cauda epididymis) | 60.00 ± 4.43 | 68.75 ± 6.84 | 62.15 ± 5.53 | 42.40 ± 2.02*
Sperm (10^6^/g cauda epididymis) | 402 ± 29 | 443 ± 46 | 400 ± 32 | 283 ± 13*

* Significantly different (P ≤ 0.05) from the control group by Shirley’s or Dunn’s test.

** Significantly different (P ≤ 0.01) from the control group by Williams’ test.

^a^ Data are presented as mean ± standard error. Differences from the control group are not significant by Dunnett’s test (tissue weights) or Dunn’s test (spermatid measurements and sperm motility).

Table D-2 Estrous Cycle Characterization for Female Rats in the Three-month Drinking Water Study of o-Chloropyridine^a^

| 0 ppm | 100 ppm | 300 ppm | 1,000 ppm
Number weighed at necropsy | 10 | 10 | 10 | 10
Necropsy body wt (g) | 195 ± 4 | 196 ± 2 | 190 ± 3 | 174 ± 2**
Proportion of regular cycling females^b^ | 9/10 | 10/10 | 8/10 | 9/10
Estrous cycle length (days) | 5.50 ± 0.27 | 5.00 ± 0.15 | 5.50 ± 0.24^c^ | 5.90 ± 0.18
Estrous stages (% of cycle)
Diestrus | 53.3 | 54.2 | 62.5 | 61.7
Proestrus | 15.0 | 14.2 | 11.7 | 13.3
Estrus | 23.3 | 20.8 | 20.8 | 19.2
Metestrus | 8.3 | 10.8 | 5.0 | 5.8

** Significantly different (P ≤ 0.01) from the control group by Williams’ test.

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error. Differences from the control group are not significant by Dunn’s test (estrous cycle length). By multivariate analysis of variance, exposed females do not differ significantly from the control females in the relative length of time spent in the estrous stages. Tests for equality of transition probability matrices among all groups and between the control group and each exposed group indicated 300 ppm females had a higher proportion of extended diestrus than control females.

^b^ Number of females with a regular cycle/number of females cycling.

^c^ Estrous cycle was longer than 12 days or unclear in 1 of 10 animals.

Table D-3 Results of Vaginal Cytology Study Using the Transition Matrix Approach for Female Rats in the Three-month Drinking Water Study of o-Chloropyridine

Stage | Comparison | P Value | Trend^a^
Overall tests | Overall | 0.024
Overall tests | 100 ppm vs. controls | 0.257 | N
Overall tests | 300 ppm vs. controls | 0.009 | –
Overall tests | 1,000 vs. controls | 0.32 | –
Extended estrus | Overall | 0.721
Extended estrus | 100 ppm vs. controls | 0.305 | N
Extended estrus | 300 ppm vs. controls | 0.595 | N
Extended estrus | 1,000 vs. controls | 0.878 | N
Extended diestrus | Overall | 0.039
Extended diestrus | 100 ppm vs. controls | 0.695 | N
Extended diestrus | 300 ppm vs. controls | 0.008 | –
Extended diestrus | 1,000 vs. controls | 0.249 | –
Extended metestrus | Overall | 1
Extended metestrus | 100 ppm vs. controls | 1 | –
Extended metestrus | 300 ppm vs. controls | 1 | –
Extended metestrus | 1,000 vs. controls | 1 | –
Extended proestrus | Overall | 1
Extended proestrus | 100 ppm vs. controls | 1 | –
Extended proestrus | 300 ppm vs. controls | 1 | –
Extended Proestrus | 1,000 vs. controls | 1 | –
Skipped estrus | Overall | 1
Skipped estrus | 100 ppm vs. controls | 1 | –
Skipped estrus | 300 ppm vs. controls | 1 | –
Skipped estrus | 1,000 vs. controls | 1 | –
Skipped diestrus | Overall | 1
Skipped diestrus | 100 ppm vs. controls | 1 | –
Skipped diestrus | 300 ppm vs. controls | 1 | –
Skipped diestrus | 1,000 vs. controls | 1 | –
Overall tests | 300 ppm vs. controls | 0.009 | –
Extended diestrus | 300 ppm vs. controls | 0.008 | –

^a^ N means that the exposed group had a lower probability of transitioning to and/or from the relevant abnormal state (extended estrus, extended metestrus, extended proestrus, skipped estrus, or skipped diestrus) than did the control group.

Table D-4 Summary of Reproductive Tissue Evaluations for Male Mice in the Three-month Drinking Water Study of o-Chloropyridine^a^

| 0 ppm | 100 ppm | 300 ppm | 1,000 ppm
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 40.8 ± 0.9 | 40.2 ± 1.2 | 40.5 ± 1.2 | 33.0 ± 0.5**
L. Cauda epididymis | 0.0200 ± 0.0010 | 0.0194 ± 0.0012 | 0.0173 ± 0.0008 | 0.0201 ± 0.0009
L. Epididymis | 0.0509 ± 0.0019 | 0.0545 ± 0.0017 | 0.0548 ± 0.0019 | 0.0530 ± 0.0020
L. Testis | 0.1133 ± 0.0020 | 0.1132 ± 0.0012 | 0.1158 ± 0.0022 | 0.1101 ± 0.0022
Spermatid measurements
Spermatid heads (10^6^/testis) | 19.87 ± 0.88 | 19.39 ± 0.91 | 20.32 ± 0.60 | 19.84 ± 0.70
Spermatid heads (10^6^/g testis) | 195.3 ± 9.0 | 186.4 ± 8.0 | 190.1 ± 2.2 | 194.8 ± 5.2
Epididymal spermatozoal measurements
Sperm motility (%) | 74.1 ± 1.3 | 72.8 ± 3.7 | 72.0 ± 1.7 | 69.6 ± 2.7
Sperm (10^6^/cauda epididymis) | 8.99 ± 1.25 | 10.29 ± 0.95 | 6.92 ± 0.80 | 8.99 ± 1.36
Sperm (10^6^/g cauda epididymis) | 460 ± 68 | 554 ± 64 | 403 ± 43 | 444 ± 61

** Significantly different (P ≤ 0.01) from the control group by Williams’ test.

^a^ Data are presented as mean ± standard error. Differences from the control group are not significant by Dunnett’s test (tissue weights) or Dunn’s test (spermatid and epididymal spermatozoal measurements).

Table D-5 Estrous Cycle Characterization for Female Mice in the Three-month Drinking Water Study of o-Chloropyridine^a^

| 0 ppm | 100 ppm | 300 ppm | 1,000 ppm
Number weighed at necropsy | 9 | 10 | 10 | 10
Necropsy body wt (g) | 28.5 ± 1.4 | 30.3 ± 1.1 | 31.9 ± 0.8 | 28.4 ± 0.6
Proportion of regular cycling females^b^ | 6/9 | 6/10 | 8/10 | 6/10
Estrous cycle length (days) | 3.86 ± 0.14^c^ | 4.45 ± 0.17 | 3.91 ± 0.14 | 5.05 ± 0.59
Estrous stages (% of cycle)
Diestrus | 42.6 | 30.8 | 32.5 | 36.7
Proestrus | 0.0 | 0.0 | 0.0 | 0.0
Estrus | 39.8 | 47.5 | 46.7 | 42.5
Metestrus | 17.6 | 21.7 | 20.8 | 20.8

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error. Differences from the control group are not significant by Dunnett’s test (body weight) or Dunn’s test (estrous cycle length). By multivariate analysis of variance, exposed females do not differ significantly from the control females in the relative length of time spent in the estrous stages. Tests for equality of transition probability matrices among all groups and between the control group and each exposed group indicated exposed females did not have significantly higher proportions of extended estrus or diestrus than control females.

^b^ Number of females with a regular cycle/number of females cycling.

^c^ Estrous cycle was longer than 12 days or unclear in 2 of 9 animals.

Table D-6 Results of Vaginal Cytology Study Using the Transition Matrix Approach for Female Mice in the Three-month Drinking Water Study of o-Chloropyridine

Stage | Comparison | P Value | Trend^a^
Overall tests | Overall | <0.001
Overall tests | 100 ppm vs. controls | <0.001 | –
Overall tests | 300 ppm vs. controls | 0.088 | N
Overall tests | 1,000 vs. controls | 0.048 | –
Extended estrus | Overall | 0.236
Extended estrus | 100 ppm vs. controls | 0.234 | –
Extended estrus | 300 ppm vs. controls | 0.361 | –
Extended estrus | 1,000 vs. controls | 0.214 | –
Extended diestrus | Overall | 0.074
Extended diestrus | 100 ppm vs. controls | 0.033 | N
Extended diestrus | 300 ppm vs. controls | 0.131 | N
Extended diestrus | 1,000 vs. controls | 0.748 | N
Extended metestrus | Overall | 1
Extended metestrus | 100 ppm vs. controls | 1 | –
Extended metestrus | 300 ppm vs. controls | 1 | –
Extended metestrus | 1,000 vs. controls | 1 | –
Extended proestrus | Overall | 1
Extended proestrus | 100 ppm vs. controls | 1 | –
Extended proestrus | 300 ppm vs. controls | 1 | –
Extended Proestrus | 1,000 vs. controls | 1 | –
Skipped estrus | Overall | 1
Skipped estrus | 100 ppm vs. controls | 1 | –
Skipped estrus | 300 ppm vs. controls | 1 | –
Skipped estrus | 1,000 vs. controls | 1 | –
Skipped diestrus | Overall | 0.521
Skipped diestrus | 100 ppm vs. controls | 0.289 | N
Skipped diestrus | 300 ppm vs. controls | 0.289 | N
Skipped diestrus | 1,000 vs. controls | 0.916 | N
Overall tests | 100 ppm vs. controls | <0.001 | –
Overall tests | 1,000 ppm vs. controls | 0.048 | –
Extended diestrus | 100 ppm vs. controls | 0.033 | N

^a^ N means that the exposed group had a lower probability of transitioning to and/or from the relevant abnormal state (extended estrus, extended metestrus, extended proestrus, skipped estrus, or skipped diestrus) than did the control group.

Figure D-1

Vaginal Cytology Plots for Female Rats in the Three-month Drinking Water Study of o-Chloropyridine

Daily vaginal lavage samples were collected from each animal and estrous stage determined based on vaginal cytology. Individual females are aligned by their second estrus, and color coded based on estrous stage to aid in visual comparisons amongst the groups. D = diestrus, P = proestrus, E = estrus, M = metestrus.

Figure D-2

Vaginal Cytology Plots for Female Mice in the Three-month Drinking Water Study of o-Chloropyridine

Daily vaginal lavage samples were collected from each animal and estrous stage determined based on vaginal cytology. Individual females are aligned by their second estrus, and color coded based on estrous stage to aid in visual comparisons amongst the groups. D = diestrus, P = proestrus, E = estrus, M = metestrus.