# Appendix C Organ Weights and Organ-Weight-to-Body-Weight Ratios

Table C-1 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the Two-week Dermal Study of o-Chloropyridine^a^

| Vehicle Control | 6.25 mg/kg | 12.5 mg/kg | 25 mg/kg | 50 mg/kg | 100 mg/kg
n | 5 | 5 | 5 | 5 | 5 | 5
Male
Necropsy body wt | 157 ± 6 | 159 ± 6 | 157 ± 4 | 153 ± 3 | 158 ± 5 | 158 ± 4
Heart
Absolute | 0.60 ± 0.02 | 0.61 ± 0.02 | 0.59 ± 0.02 | 0.60 ± 0.01 | 0.65 ± 0.04 | 0.60 ± 0.01
Relative | 3.819 ± 0.079 | 3.829 ± 0.074 | 3.752 ± 0.080 | 3.920 ± 0.045 | 4.131 ± 0.250 | 3.823 ± 0.100
R. Kidney
Absolute | 0.69 ± 0.03 | 0.71 ± 0.03 | 0.72 ± 0.02 | 0.68 ± 0.03 | 0.73 ± 0.03 | 0.73 ± 0.02
Relative | 4.408 ± 0.089 | 4.439 ± 0.073 | 4.572 ± 0.059 | 4.436 ± 0.152 | 4.623 ± 0.084 | 4.604 ± 0.104
Liver
Absolute | 8.02 ± 0.28 | 8.13 ± 0.18 | 8.25 ± 0.23 | 8.03 ± 0.16 | 8.87 ± 0.35* | 8.79 ± 0.11*
Relative | 51.083 ± 0.188 | 51.251 ± 0.857 | 52.473 ± 1.018 | 52.428 ± 0.422 | 55.961 ± 0.567** | 55.732 ± 0.777**
Lung
Absolute | 1.00 ± 0.05 | 1.13 ± 0.16 | 1.06 ± 0.06 | 0.98 ± 0.04 | 1.09 ± 0.07 | 0.79 ± 0.18
Relative | 6.353 ± 0.107 | 7.001 ± 0.731 | 6.725 ± 0.277 | 6.413 ± 0.420 | 6.866 ± 0.421 | 5.088 ± 1.133
R. Testis
Absolute | 0.996 ± 0.035 | 1.001 ± 0.034 | 1.028 ± 0.022 | 0.970 ± 0.036 | 1.011 ± 0.031 | 0.983 ± 0.047
Relative | 6.346 ± 0.134 | 6.296 ± 0.096 | 6.559 ± 0.269 | 6.324 ± 0.128 | 6.391 ± 0.136 | 6.217 ± 0.180
Thymus
Absolute | 0.471 ± 0.022 | 0.463 ± 0.018 | 0.455 ± 0.010 | 0.483 ± 0.015 | 0.475 ± 0.016 | 0.466 ± 0.021
Relative | 2.999 ± 0.099 | 2.912 ± 0.068 | 2.898 ± 0.054 | 3.151 ± 0.038 | 3.012 ± 0.127 | 2.958 ± 0.148
Female
Necropsy body wt | 120 ± 2 | 121 ± 1 | 120 ± 3 | 122 ± 4 | 120 ± 2 | 120 ± 2
Heart
Absolute | 0.48 ± 0.01 | 0.50 ± 0.02 | 0.51 ± 0.01 | 0.49 ± 0.02 | 0.48 ± 0.01 | 0.50 ± 0.01
Relative | 4.007 ± 0.098 | 4.094 ± 0.135 | 4.205 ± 0.060 | 4.041 ± 0.054 | 4.009 ± 0.112 | 4.120 ± 0.059
R. Kidney
Absolute | 0.57 ± 0.02 | 0.61 ± 0.01 | 0.59 ± 0.01 | 0.60 ± 0.02 | 0.58 ± 0.01 | 0.58 ± 0.01
Relative | 4.729 ± 0.050 | 4.994 ± 0.095 | 4.929 ± 0.066 | 4.945 ± 0.051 | 4.844 ± 0.060 | 4.798 ± 0.109
Liver
Absolute | 5.64 ± 0.14 | 5.85 ± 0.17 | 5.91 ± 0.17 | 6.03 ± 0.30 | 5.69 ± 0.10 | 6.20 ± 0.11b
Relative | 47.053 ± 1.335 | 48.238 ± 1.369 | 49.157 ± 1.602 | 49.495 ± 0.914 | 47.564 ± 0.707 | 51.537 ± 0.476^b^
Lung
Absolute | 0.81 ± 0.02 | 0.84 ± 0.02 | 0.85 ± 0.05 | 0.82 ± 0.02 | 0.83 ± 0.02 | 0.84 ± 0.03
Relative | 6.716 ± 0.216 | 6.955 ± 0.174 | 7.036 ± 0.365 | 6.754 ± 0.120 | 6.901 ± 0.210 | 6.979 ± 0.222
Thymus
Absolute | 0.374 ± 0.012 | 0.411 ± 0.025 | 0.385 ± 0.011 | 0.379 ± 0.027 | 0.390 ± 0.008 | 0.371 ± 0.018
Relative | 3.115 ± 0.104 | 3.389 ± 0.212 | 3.202 ± 0.090 | 3.105 ± 0.122 | 3.258 ± 0.076 | 3.080 ± 0.097

* Significantly different (P ≤ 0.05) from the vehicle control group by Williams’ test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

^b^ n = 4.

Table C-2 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the Three-month Drinking Water Study of o-Chloropyridine^a^

| 0 ppm | 10 ppm | 30 ppm | 100 ppm | 300 ppm | 1,000 ppm
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 320 ± 6 | 326 ± 7 | 326 ± 8 | 326 ± 8 | 309 ± 7 | 268 ± 6**
Heart
Absolute | 0.90 ± 0.02 | 0.93 ± 0.03 | 0.90 ± 0.03^b^ | 0.94 ± 0.03 | 0.90 ± 0.02 | 0.83 ± 0.01
Relative | 2.806 ± 0.032 | 2.854 ± 0.048 | 2.791 ± 0.022^b^ | 2.890 ± 0.079 | 2.898 ± 0.032 | 3.089 ± 0.046**
R. Kidney
Absolute | 0.95 ± 0.01 | 1.02 ± 0.02* | 1.04 ± 0.03* | 1.01 ± 0.02* | 1.02 ± 0.03* | 1.07 ± 0.02**
Relative | 2.978 ± 0.065 | 3.144 ± 0.036* | 3.172 ± 0.052* | 3.110 ± 0.081 | 3.304 ± 0.030** | 4.012 ± 0.052**
Liver
Absolute | 10.91 ± 0.29 | 11.76 ± 0.29 | 10.87 ± 0.78 | 13.17 ± 0.35** | 13.51 ± 0.40** | 14.33 ± 0.36**
Relative | 34.101 ± 0.737 | 36.114 ± 0.615 | 33.092 ± 1.788 | 40.530 ± 1.053** | 43.672 ± 0.620** | 53.553 ± 0.653**
Lung
Absolute | 1.34 ± 0.05 | 1.35 ± 0.04 | 1.45 ± 0.09 | 1.32 ± 0.05 | 1.32 ± 0.04 | 1.21 ± 0.05
Relative | 4.186 ± 0.150 | 4.124 ± 0.069 | 4.422 ± 0.185 | 4.061 ± 0.154 | 4.261 ± 0.113 | 4.493 ± 0.114
R. Testis
Absolute | 1.344 ± 0.030 | 1.394 ± 0.029 | 1.404 ± 0.021 | 1.457 ± 0.028* | 1.421 ± 0.025 | 1.423 ± 0.022
Relative | 4.212 ± 0.118 | 4.282 ± 0.051 | 4.323 ± 0.100 | 4.490 ± 0.121 | 4.611 ± 0.090** | 5.330 ± 0.091**
Thymus
Absolute | 0.317 ± 0.014 | 0.327 ± 0.009 | 0.317 ± 0.010 | 0.314 ± 0.011 | 0.309 ± 0.014 | 0.256 ± 0.008**
Relative | 0.990 ± 0.040 | 1.005 ± 0.032 | 0.979 ± 0.043 | 0.968 ± 0.039 | 0.999 ± 0.038 | 0.959 ± 0.030
Female
Necropsy body wt | 195 ± 4 | 200 ± 2 | 200 ± 4 | 196 ± 2 | 190 ± 3 | 174 ± 2**
Heart
Absolute | 0.57 ± 0.01 | 0.58 ± 0.01 | 0.61 ± 0.02 | 0.60 ± 0.02 | 0.59 ± 0.01 | 0.57 ± 0.01
Relative | 2.915 ± 0.034 | 2.907 ± 0.035 | 3.043 ± 0.065 | 3.074 ± 0.083 | 3.093 ± 0.064* | 3.249 ± 0.031**
R. Kidney
Absolute | 0.65 ± 0.02 | 0.67 ± 0.01 | 0.70 ± 0.01* | 0.69 ± 0.02* | 0.71 ± 0.01** | 0.74 ± 0.01**
Relative | 3.317 ± 0.047 | 3.347 ± 0.032 | 3.472 ± 0.050* | 3.530 ± 0.051** | 3.714 ± 0.058** | 4.259 ± 0.040**
Liver
Absolute | 5.80 ± 0.22 | 6.14 ± 0.14 | 6.77 ± 0.17** | 6.89 ± 0.12** | 7.94 ± 0.34** | 9.06 ± 0.21**
Relative | 29.632 ± 0.735 | 30.698 ± 0.619 | 33.784 ± 0.410** | 35.152 ± 0.373** | 41.684 ± 1.375** | 52.086 ± 0.597**
Lung
Absolute | 0.93 ± 0.02 | 0.95 ± 0.02 | 0.96 ± 0.02 | 0.96 ± 0.02 | 0.95 ± 0.02 | 0.87 ± 0.01
Relative | 4.760 ± 0.095 | 4.745 ± 0.118 | 4.818 ± 0.118 | 4.914 ± 0.074 | 5.002 ± 0.103 | 5.027 ± 0.091
Thymus
Absolute | 0.235 ± 0.008 | 0.242 ± 0.009 | 0.240 ± 0.006 | 0.247 ± 0.016 | 0.243 ± 0.010 | 0.206 ± 0.006
Relative | 1.206 ± 0.037 | 1.211 ± 0.044 | 1.198 ± 0.031 | 1.265 ± 0.087 | 1.276 ± 0.046 | 1.189 ± 0.037

* Significantly different (P ≤ 0.05) from the control group by Williams’ test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

^b^ n = 9.

Table C-3 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Two-week Dermal Study of o-Chloropyridine^a^

| Vehicle Control | 6.25 mg/kg | 12.5 mg/kg | 25 mg/kg | 50 mg/kg | 100 mg/kg
n | 5 | 5 | 5 | 5 | 5 | 5
Male
Necropsy body wt | 25.7 ± 0.3 | 26.4 ± 0.5 | 26.8 ± 0.4 | 26.1 ± 0.5 | 25.7 ± 0.3 | 25.6 ± 0.7
Heart
Absolute | 0.13 ± 0.01 | 0.13 ± 0.00 | 0.14 ± 0.00 | 0.14 ± 0.01 | 0.13 ± 0.00 | 0.13 ± 0.01
Relative | 5.009 ± 0.181 | 5.046 ± 0.070 | 5.088 ± 0.079 | 5.218 ± 0.136 | 5.230 ± 0.069 | 5.182 ± 0.129
R. Kidney
Absolute | 0.26 ± 0.00 | 0.27 ± 0.01 | 0.28 ± 0.00 | 0.28 ± 0.01 | 0.28 ± 0.01 | 0.28 ± 0.01
Relative | 10.059 ± 0.254 | 10.379 ± 0.134 | 10.608 ± 0.230 | 10.544 ± 0.316 | 10.940 ± 0.277* | 10.921 ± 0.248*
Liver
Absolute | 1.48 ± 0.02 | 1.51 ± 0.02 | 1.51 ± 0.03 | 1.50 ± 0.04 | 1.50 ± 0.01 | 1.53 ± 0.04
Relative | 57.443 ± 0.881 | 57.168 ± 0.753 | 56.504 ± 1.101 | 57.429 ± 1.473 | 58.181 ± 0.698 | 59.948 ± 1.673
Lung
Absolute | 0.16 ± 0.01 | 0.20 ± 0.02 | 0.18 ± 0.02 | 0.18 ± 0.01 | 0.17 ± 0.01 | 0.18 ± 0.01
Relative | 6.095 ± 0.472 | 7.599 ± 0.625 | 6.870 ± 0.831 | 6.827 ± 0.514 | 6.716 ± 0.303 | 6.926 ± 0.305
R. Testis
Absolute | 0.110 ± 0.003 | 0.105 ± 0.004 | 0.106 ± 0.004 | 0.108 ± 0.003 | 0.113 ± 0.003 | 0.103 ± 0.004
Relative | 4.265 ± 0.131 | 3.974 ± 0.153 | 3.979 ± 0.158 | 4.130 ± 0.068 | 4.390 ± 0.118 | 4.042 ± 0.084
Thymus
Absolute | 0.054 ± 0.003 | 0.054 ± 0.001 | 0.052 ± 0.003 | 0.046 ± 0.001 | 0.053 ± 0.002 | 0.054 ± 0.005
Relative | 2.101 ± 0.104 | 2.036 ± 0.040 | 1.940 ± 0.090 | 1.774 ± 0.067 | 2.066 ± 0.096 | 2.103 ± 0.150
Female
Necropsy body wt | 23.2 ± 0.6 | 23.1 ± 0.4 | 22.8 ± 0.6 | 23.0 ± 0.6 | 22.7 ± 0.6 | 23.3 ± 0.4
Heart
Absolute | 0.13 ± 0.01 | 0.13 ± 0.01 | 0.13 ± 0.01 | 0.13 ± 0.00 | 0.13 ± 0.00 | 0.13 ± 0.00
Relative | 5.411 ± 0.164 | 5.498 ± 0.130 | 5.589 ± 0.091 | 5.679 ± 0.052 | 5.646 ± 0.140 | 5.595 ± 0.099
R. Kidney
Absolute | 0.20 ± 0.01 | 0.20 ± 0.01 | 0.20 ± 0.00 | 0.21 ± 0.01 | 0.20 ± 0.01 | 0.21 ± 0.01
Relative | 8.383 ± 0.185 | 8.835 ± 0.119 | 8.598 ± 0.185 | 9.074 ± 0.133* | 8.613 ± 0.194 | 8.849 ± 0.172
Liver
Absolute | 1.37 ± 0.05 | 1.36 ± 0.06 | 1.28 ± 0.04 | 1.38 ± 0.08 | 1.32 ± 0.04 | 1.47 ± 0.01
Relative | 58.806 ± 0.979 | 58.610 ± 1.496 | 56.121 ± 1.307 | 60.054 ± 2.197 | 58.148 ± 0.773 | 63.336 ± 1.070
Lung
Absolute | 0.18 ± 0.01 | 0.21 ± 0.01 | 0.18 ± 0.01 | 0.19 ± 0.01 | 0.18 ± 0.01 | 0.18 ± 0.01
Relative | 7.763 ± 0.474 | 8.875 ± 0.383 | 8.060 ± 0.386 | 8.176 ± 0.604 | 7.969 ± 0.324 | 7.576 ± 0.297
Thymus
Absolute | 0.075 ± 0.003 | 0.070 ± 0.002 | 0.066 ± 0.002 | 0.071 ± 0.003 | 0.079 ± 0.004 | 0.077 ± 0.006
Relative | 3.231 ± 0.083 | 3.056 ± 0.136 | 2.900 ± 0.079 | 3.107 ± 0.202 | 3.475 ± 0.089 | 3.316 ± 0.194

* Significantly different (P ≤ 0.05) from the vehicle control group by Williams’ or Dunnett’s test.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Table C-4 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Three-month Drinking Water Study of o-Chloropyridine^a^

| 0 ppm | 10 ppm | 30 ppm | 100 ppm | 300 ppm | 1,000 ppm
Male
n | 10 | 10 | 10 | 10 | 10 | 10
Necropsy body wt | 40.8 ± 0.9 | 42.4 ± 1.1 | 42.4 ± 0.6 | 40.2 ± 1.2 | 40.5 ± 1.2 | 33.0 ± 0.5**
Heart
Absolute | 0.17 ± 0.00 | 0.17 ± 0.00 | 0.18 ± 0.00 | 0.17 ± 0.00 | 0.17 ± 0.00 | 0.15 ± 0.00**
Relative | 4.116 ± 0.070 | 4.108 ± 0.112 | 4.293 ± 0.089 | 4.169 ± 0.091 | 4.129 ± 0.105 | 4.573 ± 0.059**
R. Kidney
Absolute | 0.34 ± 0.01 | 0.35 ± 0.01 | 0.35 ± 0.01 | 0.35 ± 0.01 | 0.35 ± 0.01 | 0.31 ± 0.01
Relative | 8.237 ± 0.218 | 8.203 ± 0.090 | 8.193 ± 0.244 | 8.631 ± 0.217 | 8.556 ± 0.229 | 9.242 ± 0.369*
Liver
Absolute | 1.70 ± 0.06 | 1.89 ± 0.07* | 1.95 ± 0.04* | 1.84 ± 0.07* | 2.01 ± 0.08** | 1.95 ± 0.05**
Relative | 41.624 ± 0.778 | 44.531 ± 0.718* | 45.851 ± 0.819** | 45.766 ± 0.974** | 49.467 ± 0.796** | 59.121 ± 0.830**
Lung
Absolute | 0.28 ± 0.02 | 0.27 ± 0.02 | 0.26 ± 0.02 | 0.27 ± 0.02 | 0.29 ± 0.02 | 0.29 ± 0.01
Relative | 6.824 ± 0.375 | 6.479 ± 0.445 | 6.230 ± 0.489 | 6.806 ± 0.423 | 7.248 ± 0.507 | 8.676 ± 0.441**
R. Testis
Absolute | 0.119 ± 0.001 | 0.119 ± 0.002 | 0.121 ± 0.002 | 0.117 ± 0.002 | 0.120 ± 0.003 | 0.116 ± 0.004
Relative | 2.926 ± 0.047 | 2.810 ± 0.067 | 2.857 ± 0.046 | 2.945 ± 0.102 | 2.969 ± 0.079 | 3.502 ± 0.093**
Thymus
Absolute | 0.054 ± 0.004 | 0.061 ± 0.006^b^ | 0.054 ± 0.002 | 0.052 ± 0.002 | 0.057 ± 0.004 | 0.043 ± 0.002
Relative | 1.328 ± 0.075 | 1.428 ± 0.123^b^ | 1.264 ± 0.054 | 1.293 ± 0.047 | 1.401 ± 0.097 | 1.308 ± 0.069
Female
n | 9 | 10 | 10 | 10 | 10 | 10
Necropsy body wt | 28.5 ± 1.4 | 31.8 ± 1.0 | 31.2 ± 1.3 | 30.3 ± 1.1 | 31.9 ± 0.8 | 28.4 ± 0.6
Heart
Absolute | 0.13 ± 0.01 | 0.13 ± 0.00 | 0.13 ± 0.00 | 0.12 ± 0.00 | 0.13 ± 0.00 | 0.13 ± 0.00
Relative | 4.511 ± 0.153 | 4.038 ± 0.143* | 4.181 ± 0.134 | 4.130 ± 0.131 | 4.102 ± 0.092 | 4.494 ± 0.063
R. Kidney
Absolute | 0.19 ± 0.01 | 0.20 ± 0.00 | 0.19 ± 0.01 | 0.19 ± 0.01 | 0.20 ± 0.00 | 0.22 ± 0.01**
Relative | 6.866 ± 0.352 | 6.203 ± 0.206 | 6.212 ± 0.170 | 6.232 ± 0.174 | 6.321 ± 0.154 | 7.676 ± 0.156*
Liver
Absolute | 1.22 ± 0.09 | 1.37 ± 0.04 | 1.34 ± 0.05 | 1.35 ± 0.07 | 1.62 ± 0.05** | 1.94 ± 0.0.05**
Relative | 42.778 ± 1.560 | 43.065 ± 1.066 | 43.266 ± 0.645 | 44.466 ± 1.122 | 50.818 ± 1.290** | 68.154 ± 1.026**
Lung
Absolute | 0.25 ± 0.02 | 0.27 ± 0.02 | 0.25 ± 0.02 | 0.23 ± 0.01 | 0.24 ± 0.01 | 0.23 ± 0.01
Relative | 8.952 ± 0.699 | 8.502 ± 0.795 | 7.981 ± 0.537 | 7.523 ± 0.440 | 7.535 ± 0.324 | 7.987 ± 0.380
Thymus
Absolute | 0.049 ± 0.004 | 0.056 ± 0.003 | 0.054 ± 0.003 | 0.054 ± 0.002 | 0.053 ± 0.002 | 0.045 ± 0.002
Relative | 1.715 ± 0.111 | 1.762 ± 0.123 | 1.722 ± 0.077 | 1.812 ± 0.073 | 1.679 ± 0.072 | 1.578 ± 0.077

* Significantly different (P ≤ 0.05) from the control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

^b^ n = 9.