# Appendix B Clinical Pathology Results

Table B-1 Hematology and Clinical Chemistry Data for Rats in the Three-month Drinking Water Study of o-Chloropyridine^a^

| 0 ppm | 10 ppm | 30 ppm | 100 ppm | 300 ppm | 1,000 ppm
Male
Hematology
n
Day 4 | 10 | 10 | 10 | 9 | 9 | 10
Day 22 | 10 | 10 | 10 | 10 | 10 | 10
Week 14 | 9 | 10 | 10 | 10 | 10 | 10
Hematocrit (%)
Day 4 | 40.0 ± 0.4 | 39.8 ± 0.4 | 40.5 ± 0.6 | 38.8 ± 0.5 | 39.6 ± 0.5 | 43.3 ± 0.9*
Day 22 | 43.4 ± 0.4 | 42.7 ± 0.4 | 42.6 ± 0.4 | 41.2 ± 0.6** | 41.5 ± 0.5** | 39.6 ± 0.4**
Week 14 | 45.5 ± 0.6 | 45.2 ± 0.3 | 46.3 ± 0.3 | 44.5 ± 0.9 | 42.9 ± 0.4** | 41.7 ± 0.4**
Hemoglobin (g/dL)
Day 4 | 13.4 ± 0.1 | 13.4 ± 0.1 | 13.6 ± 0.2 | 13.1 ± 0.2 | 13.3 ± 0.2 | 14.5 ± 0.3*
Day 22 | 14.8 ± 0.1 | 14.5 ± 0.1 | 14.5 ± 0.1 | 14.1 ± 0.2** | 14.1 ± 0.2** | 13.5 ± 0.1**
Week 14 | 15.2 ± 0.2 | 15.1 ± 0.1 | 15.4 ± 0.1 | 15.0 ± 0.3 | 14.4 ± 0.1** | 13.9 ± 0.1**
Erythrocytes (10^6^/μL)
Day 4 | 6.80 ± 0.08 | 6.85 ± 0.10 | 6.92 ± 0.10 | 6.72 ± 0.09 | 6.95 ± 0.10 | 7.53 ± 0.14**
Day 22 | 7.50 ± 0.07 | 7.35 ± 0.09 | 7.37 ± 0.08 | 7.18 ± 0.11* | 7.30 ± 0.08 | 7.25 ± 0.08
Week 14 | 8.91 ± 0.11 | 8.75 ± 0.07 | 9.04 ± 0.08 | 8.76 ± 0.15 | 8.51 ± 0.06** | 8.42 ± 0.09**
Reticulocytes (10^6^/μL)
Day 4 | 0.46 ± 0.04 | 0.45 ± 0.04 | 0.54 ± 0.02 | 0.50 ± 0.05 | 0.46 ± 0.03 | 0.39 ± 0.02
Day 22 | 0.33 ± 0.04 | 0.33 ± 0.02 | 0.28 ± 0.02 | 0.30 ± 0.02 | 0.36 ± 0.04 | 0.41 ± 0.02
Week 14 | 0.26 ± 0.01 | 0.27 ± 0.02 | 0.27 ± 0.02 | 0.25 ± 0.02 | 0.37 ± 0.02** | 0.32 ± 0.03*
Mean cell volume (fL)
Day 4 | 58.8 ± 0.3 | 58.1 ± 0.2 | 58.5 ± 0.3 | 57.8 ± 0.3* | 56.9 ± 0.2** | 57.5 ± 0.2**
Day 22 | 57.9 ± 0.3 | 58.0 ± 0.3 | 57.7 ± 0.2 | 57.3 ± 0.3 | 56.8 ± 0.3** | 54.7 ± 0.2**
Week 14 | 51.2 ± 0.2 | 51.6 ± 0.2 | 51.3 ± 0.2 | 50.8 ± 0.3 | 50.5 ± 0.2* | 49.3 ± 0.3**
Mean cell hemoglobin (pg)
Day 4 | 19.7 ± 0.1 | 19.5 ± 0.1 | 19.6 ± 0.1 | 19.5 ± 0.1 | 19.1 ± 0.1** | 19.3 ± 0.1**
Day 22 | 19.8 ± 0.1 | 19.8 ± 0.1 | 19.7 ± 0.1 | 19.6 ± 0.1 | 19.4 ± 0.0** | 18.7 ± 0.1**
Week 14 | 17.0 ± 0.0 | 17.2 ± 0.1 | 17.1 ± 0.1 | 17.1 ± 0.1 | 16.9 ± 0.1 | 16.5 ± 0.1**
Mean cell hemoglobin concentration (g/dL)
Day 4 | 33.6 ± 0.1 | 33.6 ± 0.1 | 33.5 ± 0.1 | 33.7 ± 0.1 | 33.6 ± 0.1 | 33.5 ± 0.1
Day 22 | 34.1 ± 0.1 | 34.1 ± 0.1 | 34.0 ± 0.1 | 34.2 ± 0.1 | 34.1 ± 0.1 | 34.1 ± 0.1
Week 14 | 33.3 ± 0.1 | 33.3 ± 0.1 | 33.3 ± 0.1 | 33.6 ± 0.1 | 33.5 ± 0.1 | 33.4 ± 0.1
Platelets (10^3^/μL)
Day 4 | 640.9 ± 8.6 | 625.4 ± 25.0 | 613.4 ± 26.7 | 606.3 ± 18.3 | 605.2 ± 28.6 | 608.0 ± 29.7
Day 22 | 527.2 ± 21.0 | 518.5 ± 21.1 | 586.0 ± 19.3 | 550.9 ± 18.4 | 542.0 ± 22.3 | 501.9 ± 22.7
Week 14 | 418.8 ± 34.9 | 443.3 ± 20.3 | 501.6 ± 13.6 | 419.0 ± 29.3 | 485.4 ± 23.6 | 503.6 ± 15.8
Leukocytes (10^3^/μL)
Day 4 | 9.40 ± 0.21 | 9.02 ± 0.25 | 10.36 ± 0.29 | 9.82 ± 0.50 | 8.56 ± 0.36 | 11.62 ± 0.37**
Day 22 | 11.68 ± 0.43 | 12.03 ± 0.27 | 11.85 ± 0.29 | 11.26 ± 0.65 | 11.83 ± 0.44 | 10.68 ± 0.44
Week 14 | 10.30 ± 0.82 | 11.75 ± 0.50 | 12.26 ± 0.55 | 10.05 ± 0.74 | 10.88 ± 0.38 | 11.10 ± 0.48
Segmented neutrophils (10^3^/μL)
Day 4 | 0.58 ± 0.05 | 0.57 ± 0.06 | 0.66 ± 0.04 | 0.59 ± 0.08 | 0.61 ± 0.08 | 0.62 ± 0.03
Day 22 | 0.61 ± 0.05 | 0.63 ± 0.03 | 0.62 ± 0.05 | 0.50 ± 0.04 | 0.62 ± 0.03 | 0.47 ± 0.03
Week 14 | 0.56 ± 0.06 | 0.76 ± 0.11 | 0.72 ± 0.05 | 0.56 ± 0.06 | 0.55 ± 0.04 | 0.49 ± 0.03
Lymphocytes (10^3^/μL)
Day 4 | 8.58 ± 0.21 | 8.23 ± 0.24 | 9.44 ± 0.27 | 8.96 ± 0.46 | 7.70 ± 0.32 | 10.71 ± 0.35**
Day 22 | 10.80 ± 0.37 | 11.11 ± 0.23 | 10.94 ± 0.24 | 10.53 ± 0.58 | 10.94 ± 0.43 | 9.98 ± 0.42
Week 14 | 9.43 ± 0.73 | 10.51 ± 0.41 | 11.17 ± 0.51* | 9.17 ± 0.68 | 10.05 ± 0.33 | 10.33 ± 0.43
Monocytes (10^3^/μL)
Day 4 | 0.13 ± 0.01 | 0.12 ± 0.01 | 0.14 ± 0.02 | 0.16 ± 0.02 | 0.12 ± 0.01 | 0.15 ± 0.01
Day 22 | 0.13 ± 0.02 | 0.13 ± 0.01 | 0.14 ± 0.02 | 0.10 ± 0.02 | 0.13 ± 0.01 | 0.12 ± 0.01
Week 14 | 0.18 ± 0.03 | 0.23 ± 0.04 | 0.20 ± 0.03 | 0.15 ± 0.02 | 0.16 ± 0.02 | 0.19 ± 0.03
Basophils (10^3^/μL)
Day 4 | 0.104 ± 0.007 | 0.087 ± 0.006 | 0.116 ± 0.013 | 0.096 ± 0.006 | 0.094 ± 0.008 | 0.129 ± 0.010
Day 22 | 0.134 ± 0.020 | 0.144 ± 0.017 | 0.132 ± 0.008 | 0.106 ± 0.015 | 0.125 ± 0.008 | 0.102 ± 0.009
Week 14 | 0.098 ± 0.013 | 0.165 ± 0.060 | 0.124 ± 0.008 | 0.102 ± 0.014 | 0.104 ± 0.014 | 0.086 ± 0.011
Eosinophils (10^3^/μL)
Day 4 | 0.01 ± 0.00 | 0.02 ± 0.00 | 0.02 ± 0.01 | 0.02 ± 0.01 | 0.03 ± 0.01 | 0.01 ± 0.00
Day 22 | 0.02 ± 0.01 | 0.02 ± 0.00 | 0.02 ± 0.01 | 0.01 ± 0.00 | 0.02 ± 0.01 | 0.01 ± 0.00
Week 14 | 0.02 ± 0.00 | 0.08 ± 0.04 | 0.04 ± 0.01 | 0.06 ± 0.03 | 0.02 ± 0.00 | 0.01 ± 0.00
Clinical Chemistry
n | 10 | 10 | 10 | 10 | 10 | 10
Urea nitrogen (mg/dL)
Day 4 | 14.9 ± 0.6 | 15.7 ± 0.7 | 14.3 ± 0.4 | 15.4 ± 0.6 | 17.0 ± 0.7* | 19.6 ± 0.6**
Day 22 | 16.1 ± 0.5 | 14.6 ± 0.4 | 14.1 ± 0.5 | 14.2 ± 0.5 | 16.0 ± 0.7 | 15.8 ± 0.6
Week 14 | 18.5 ± 0.5 | 16.7 ± 0.5 | 17.5 ± 0.5 | 17.2 ± 0.4 | 16.6 ± 0.4 | 18.4 ± 0.5
Creatinine (mg/dL)
Day 4 | 0.29 ± 0.01 | 0.28 ± 0.01 | 0.28 ± 0.01 | 0.29 ± 0.01 | 0.27 ± 0.02 | 0.28 ± 0.01
Day 22 | 0.33 ± 0.02 | 0.31 ± 0.01 | 0.34 ± 0.02 | 0.34 ± 0.02 | 0.31 ± 0.01 | 0.28 ± 0.01
Week 14 | 0.52 ± 0.02 | 0.53 ± 0.02 | 0.53 ± 0.02 | 0.49 ± 0.02 | 0.50 ± 0.01 | 0.49 ± 0.01
Total protein (g/dL)
Day 4 | 5.7 ± 0.1 | 5.7 ± 0.0 | 5.8 ± 0.1 | 5.8 ± 0.1 | 5.9 ± 0.1 | 5.9 ± 0.1
Day 22 | 6.4 ± 0.0 | 6.4 ± 0.1 | 6.5 ± 0.1 | 6.5 ± 0.1 | 6.8 ± 0.1* | 6.6 ± 0.1
Week 14 | 7.3 ± 0.1 | 7.3 ± 0.1 | 7.5 ± 0.1 | 7.8 ± 0.1** | 8.0 ± 0.1** | 8.3 ± 0.1**
Albumin (g/dL)
Day 4 | 4.1 ± 0.0 | 4.1 ± 0.0 | 4.1 ± 0.0 | 4.1 ± 0.0 | 4.2 ± 0.0 | 4.3 ± 0.1*
Day 22 | 4.4 ± 0.0 | 4.4 ± 0.1 | 4.5 ± 0.1 | 4.6 ± 0.0** | 4.7 ± 0.1** | 4.7 ± 0.1**
Week 14 | 4.9 ± 0.0 | 4.9 ± 0.0 | 5.0 ± 0.0* | 5.2 ± 0.1** | 5.4 ± 0.1** | 5.7 ± 0.0**
Alanine aminotransferase (IU/L)
Day 4 | 51 ± 2 | 50 ± 1 | 53 ± 1 | 50 ± 2 | 55 ± 2 | 46 ± 2
Day 22 | 44 ± 1 | 41 ± 1 | 41 ± 1 | 39 ± 1** | 38 ± 1** | 44 ± 1
Week 14 | 76 ± 6 | 72 ± 5 | 70 ± 4 | 56 ± 3** | 40 ± 2** | 42 ± 2**
Alkaline phosphatase (IU/L)
Day 4 | 626 ± 13 | 622 ± 8 | 626 ± 12 | 622 ± 9 | 657 ± 10 | 701 ± 15**
Day 22 | 476 ± 8 | 486 ± 11 | 476 ± 9 | 441 ± 10* | 392 ± 8** | 392 ± 10**
Week 14 | 251 ± 9 | 234 ± 5 | 186 ± 16** | 218 ± 4** | 198 ± 4** | 195 ± 3**
Creatine kinase (IU/L)
Day 4 | 305 ± 39 | 270 ± 28 | 268 ± 20 | 553 ± 211 | 440 ± 51 | 386 ± 33
Day 22 | 324 ± 74 | 214 ± 35 | 235 ± 31 | 209 ± 31 | 190 ± 27 | 247 ± 33
Week 14 | 219 ± 36 | 196 ± 18^b^ | 177 ± 18 | 262 ± 52 | 199 ± 31 | 174 ± 16
Sorbitol dehydrogenase (IU/L)
Day 4 | 13 ± 1 | 11 ± 1 | 11 ± 1 | 10 ± 2 | 13 ± 1 | 16 ± 1
Day 22 | 15 ± 1 | 13 ± 1 | 17 ± 1 | 14 ± 1 | 16 ± 1 | 23 ± 1**
Week 14 | 33 ± 2 | 32 ± 2 | 30 ± 1 | 32 ± 2 | 30 ± 2 | 33 ± 2
Bile acids (µmol/L)
Day 4 | 23.8 ± 1.4 | 26.5 ± 2.1 | 26.4 ± 1.3 | 33.8 ± 2.2** | 49.8 ± 6.4** | 41.0 ± 5.4**
Day 22 | 25.7 ± 1.1 | 25.5 ± 1.2 | 31.0 ± 2.6 | 28.0 ± 2.0 | 34.9 ± 2.9** | 39.1 ± 2.8**
Week 14 | 31.1 ± 3.4 | 26.0 ± 1.0 | 29.0 ± 1.9 | 26.1 ± 0.8 | 33.1 ± 3.1 | 39.2 ± 2.9
Female
Hematology
n
Day 4 | 10 | 9 | 10 | 10 | 10 | 9
Day 22 | 10 | 10 | 10 | 10 | 10 | 10
Week 14 | 10 | 10 | 10 | 10 | 10 | 10
Hematocrit (%)
Day 4 | 42.6 ± 0.5 | 41.4 ± 0.5 | 42.6 ± 0.4 | 40.6 ± 1.1 | 39.8 ± 0.8* | 44.9 ± 0.8
Day 22 | 44.9 ± 0.3 | 45.9 ± 0.4 | 44.4 ± 0.4 | 43.5 ± 0.3* | 42.4 ± 0.6** | 42.4 ± 1.1**
Week 14 | 44.3 ± 0.8 | 45.2 ± 0.3 | 45.1 ± 0.3 | 43.7 ± 0.7 | 42.6 ± 0.2** | 40.7 ± 0.4**
Hemoglobin (g/dL)
Day 4 | 14.4 ± 0.2 | 14.1 ± 0.2 | 14.4 ± 0.2 | 13.8 ± 0.4 | 13.6 ± 0.3 | 15.3 ± 0.3
Day 22 | 15.5 ± 0.1 | 15.9 ± 0.1 | 15.4 ± 0.1 | 15.2 ± 0.1 | 14.8 ± 0.2* | 14.7 ± 0.4**
Week 14 | 15.1 ± 0.2 | 15.4 ± 0.1 | 15.4 ± 0.1 | 15.0 ± 0.2 | 14.7 ± 0.1* | 13.9 ± 0.2**
Erythrocytes (10^6^/μL)
Day 4 | 7.33 ± 0.09 | 7.16 ± 0.09 | 7.35 ± 0.07 | 7.02 ± 0.19 | 6.93 ± 0.15 | 7.87 ± 0.13
Day 22 | 7.80 ± 0.07 | 7.95 ± 0.08 | 7.75 ± 0.08 | 7.70 ± 0.06 | 7.51 ± 0.13 | 7.74 ± 0.17
Week 14 | 8.30 ± 0.13 | 8.50 ± 0.05 | 8.48 ± 0.07 | 8.27 ± 0.12 | 8.17 ± 0.03 | 7.90 ± 0.07**
Reticulocytes (10^6^/μL)
Day 4 | 0.36 ± 0.01 | 0.35 ± 0.03 | 0.35 ± 0.01 | 0.36 ± 0.02 | 0.32 ± 0.02 | 0.28 ± 0.01**
Day 22 | 0.20 ± 0.01 | 0.20 ± 0.01 | 0.20 ± 0.01 | 0.19 ± 0.01 | 0.22 ± 0.03 | 0.29 ± 0.02*
Week 14 | 0.23 ± 0.02 | 0.26 ± 0.02 | 0.21 ± 0.02 | 0.23 ± 0.02 | 0.26 ± 0.03 | 0.33 ± 0.02**
Mean cell volume (fL)
Day 4 | 58.0 ± 0.2 | 57.8 ± 0.2 | 57.8 ± 0.3 | 57.8 ± 0.3 | 57.6 ± 0.2 | 57.1 ± 0.2**
Day 22 | 57.5 ± 0.2 | 57.7 ± 0.2 | 57.4 ± 0.3 | 56.6 ± 0.2* | 56.6 ± 0.4* | 54.6 ± 0.2**
Week 14 | 53.5 ± 0.2 | 53.2 ± 0.1 | 53.2 ± 0.1 | 52.8 ± 0.1** | 52.1 ± 0.2** | 51.5 ± 0.2**
Mean cell hemoglobin (pg)
Day 4 | 19.7 ± 0.1 | 19.7 ± 0.1 | 19.6 ± 0.1 | 19.7 ± 0.1 | 19.7 ± 0.1 | 19.4 ± 0.1
Day 22 | 19.9 ± 0.1 | 20.0 ± 0.1 | 19.9 ± 0.1 | 19.8 ± 0.1 | 19.7 ± 0.1 | 19.0 ± 0.1**
Week 14 | 18.2 ± 0.1 | 18.1 ± 0.1 | 18.1 ± 0.1 | 18.1 ± 0.1 | 18.0 ± 0.1 | 17.6 ± 0.1**
Mean cell hemoglobin concentration (g/dL)
Day 4 | 33.8 ± 0.1 | 34.0 ± 0.1 | 33.8 ± 0.1 | 34.1 ± 0.1 | 34.3 ± 0.1* | 34.0 ± 0.1
Day 22 | 34.5 ± 0.1 | 34.6 ± 0.1 | 34.7 ± 0.1 | 35.0 ± 0.1* | 34.8 ± 0.1 | 34.7 ± 0.1
Week 14 | 34.1 ± 0.2 | 34.1 ± 0.1 | 34.1 ± 0.1 | 34.4 ± 0.1 | 34.5 ± 0.2 | 34.0 ± 0.1
Platelets (10^3^/μL)
Day 4 | 491.3 ± 17.4 | 493.4 ± 26.1 | 474.1 ± 18.2 | 530.4 ± 19.1 | 477.7 ± 22.1 | 520.8 ± 31.1
Day 22 | 457.9 ± 30.4 | 519.9 ± 15.7 | 494.0 ± 22.7 | 493.1 ± 13.2 | 466.1 ± 20.9 | 450.5 ± 25.3
Week 14 | 464.9 ± 19.1^b^ | 460.9 ± 10.7 | 519.1 ± 23.4 | 467.5 ± 25.0 | 481.8 ± 27.0 | 513.1 ± 21.5
Leukocytes (10^3^/μL)
Day 4 | 10.23 ± 0.27 | 9.24 ± 0.57 | 9.40 ± 0.62 | 9.09 ± 0.79 | 9.68 ± 0.68 | 12.54 ± 0.43*
Day 22 | 12.19 ± 0.36 | 12.38 ± 0.32 | 11.45 ± 0.38 | 11.81 ± 0.41 | 11.51 ± 0.44 | 11.40 ± 0.55
Week 14 | 9.17 ± 0.53 | 9.29 ± 0.29 | 9.15 ± 0.52 | 9.65 ± 0.47 | 9.08 ± 0.69 | 9.74 ± 0.43
Segmented neutrophils (10^3^/μL)
Day 4 | 0.61 ± 0.03 | 0.55 ± 0.05 | 0.60 ± 0.06 | 0.49 ± 0.05 | 0.52 ± 0.05 | 0.68 ± 0.05
Day 22 | 0.66 ± 0.03 | 0.63 ± 0.03 | 0.69 ± 0.06 | 0.56 ± 0.04 | 0.51 ± 0.03** | 0.52 ± 0.06*
Week 14 | 0.54 ± 0.03 | 0.67 ± 0.06 | 0.74 ± 0.09 | 0.52 ± 0.03 | 0.61 ± 0.08 | 0.58 ± 0.07
Lymphocytes (10^3^/μL)
Day 4 | 9.37 ± 0.24 | 8.49 ± 0.50 | 8.52 ± 0.55 | 8.36 ± 0.72 | 8.91 ± 0.62 | 11.49 ± 0.38
Day 22 | 11.23 ± 0.32 | 11.47 ± 0.28 | 10.45 ± 0.31 | 11.03 ± 0.36 | 10.75 ± 0.40 | 10.66 ± 0.49
Week 14 | 8.42 ± 0.51 | 8.40 ± 0.28 | 8.12 ± 0.42 | 8.89 ± 0.45 | 8.23 ± 0.63 | 8.96 ± 0.39
Monocytes (10^3^/μL)
Day 4 | 0.12 ± 0.01 | 0.11 ± 0.02 | 0.14 ± 0.02 | 0.12 ± 0.01 | 0.13 ± 0.02 | 0.17 ± 0.02
Day 22 | 0.13 ± 0.02 | 0.13 ± 0.01 | 0.13 ± 0.02 | 0.09 ± 0.01 | 0.09 ± 0.01 | 0.09 ± 0.01
Week 14 | 0.13 ± 0.02 | 0.14 ± 0.02 | 0.17 ± 0.02 | 0.15 ± 0.02 | 0.15 ± 0.03 | 0.14 ± 0.01
Basophils (10^3^/μL)
Day 4 | 0.113 ± 0.007 | 0.096 ± 0.010 | 0.117 ± 0.019 | 0.102 ± 0.011 | 0.124 ± 0.015 | 0.184 ± 0.015**
Day 22 | 0.147 ± 0.013 | 0.138 ± 0.009 | 0.164 ± 0.028 | 0.116 ± 0.013 | 0.127 ± 0.016 | 0.117 ± 0.011
Week 14 | 0.073 ± 0.018 | 0.065 ± 0.007 | 0.085 ± 0.023 | 0.067 ± 0.006 | 0.061 ± 0.012 | 0.058 ± 0.005
Eosinophils (10^3^/μL)
Day 4 | 0.02 ± 0.00 | 0.01 ± 0.00 | 0.02 ± 0.01 | 0.02 ± 0.00 | 0.02 ± 0.00 | 0.02 ± 0.00
Day 22 | 0.02 ± 0.00 | 0.02 ± 0.00 | 0.02 ± 0.01 | 0.01 ± 0.00 | 0.02 ± 0.00 | 0.01 ± 0.00
Week 14 | 0.02 ± 0.01 | 0.02 ± 0.01 | 0.03 ± 0.01 | 0.02 ± 0.00 | 0.02 ± 0.01 | 0.02 ± 0.00
Clinical Chemistry
n | 10 | 10 | 10 | 10 | 10 | 10
Urea nitrogen (mg/dL)
Day 4 | 14.1 ± 0.3 | 13.7 ± 0.8 | 13.5 ± 0.9 | 14.3 ± 0.6 | 15.4 ± 0.8 | 16.7 ± 0.6**
Day 22 | 18.9 ± 0.6 | 18.9 ± 0.8 | 18.3 ± 0.7 | 18.9 ± 0.6 | 18.8 ± 0.9 | 19.4 ± 0.7
Week 14 | 18.3 ± 0.8 | 18.9 ± 0.5 | 20.0 ± 0.7 | 18.0 ± 0.7 | 18.5 ± 0.5 | 17.5 ± 0.6
Creatinine (mg/dL)
Day 4 | 0.30 ± 0.00 | 0.29 ± 0.01 | 0.32 ± 0.01 | 0.30 ± 0.01 | 0.30 ± 0.00 | 0.27 ± 0.02
Day 22 | 0.38 ± 0.01 | 0.43 ± 0.02 | 0.37 ± 0.02 | 0.38 ± 0.01 | 0.38 ± 0.01 | 0.32 ± 0.02
Week 14 | 0.51 ± 0.02 | 0.51 ± 0.01 | 0.58 ± 0.01* | 0.52 ± 0.01 | 0.49 ± 0.02 | 0.48 ± 0.01
Total protein (g/dL)
Day 4 | 5.9 ± 0.1 | 5.8 ± 0.0 | 6.0 ± 0.1 | 5.9 ± 0.0 | 5.9 ± 0.1 | 5.8 ± 0.1
Day 22 | 6.3 ± 0.1 | 6.6 ± 0.1 | 6.5 ± 0.2 | 6.5 ± 0.1 | 6.5 ± 0.1 | 6.6 ± 0.1
Week 14 | 6.9 ± 0.1 | 7.2 ± 0.1 | 7.5 ± 0.1** | 7.4 ± 0.1** | 7.5 ± 0.1** | 7.8 ± 0.1**
Albumin (g/dL)
Day 4 | 4.3 ± 0.0 | 4.3 ± 0.0 | 4.5 ± 0.0* | 4.3 ± 0.0 | 4.3 ± 0.0 | 4.4 ± 0.1
Day 22 | 4.6 ± 0.1 | 4.7 ± 0.0 | 4.7 ± 0.1 | 4.8 ± 0.1** | 4.8 ± 0.1* | 4.9 ± 0.1**
Week 14 | 5.1 ± 0.2 | 5.1 ± 0.1 | 5.3 ± 0.1* | 5.4 ± 0.1** | 5.4 ± 0.1** | 5.7 ± 0.1**
Alanine aminotransferase (IU/L)
Day 4 | 46 ± 1 | 45 ± 1 | 48 ± 2 | 47 ± 1 | 50 ± 1 | 44 ± 2
Day 22 | 35 ± 1 | 38 ± 1 | 37 ± 2 | 36 ± 1 | 34 ± 1 | 35 ± 1
Week 14 | 72 ± 6 | 75 ± 9 | 85 ± 8 | 45 ± 2** | 43 ± 2** | 31 ± 1**
Alkaline phosphatase (IU/L)
Day 4 | 541 ± 8 | 544 ± 5 | 557 ± 9 | 554 ± 9 | 567 ± 19 | 575 ± 21
Day 22 | 416 ± 9 | 421 ± 9 | 399 ± 8 | 392 ± 7 | 337 ± 13** | 356 ± 13**
Week 14 | 207 ± 10 | 188 ± 5 | 177 ± 3** | 165 ± 4** | 170 ± 10** | 146 ± 3**
Creatine kinase (IU/L)
Day 4 | 270 ± 44 | 255 ± 32 | 298 ± 47^b^ | 321 ± 55 | 272 ± 27 | 374 ± 35
Day 22 | 275 ± 39 | 292 ± 59 | 182 ± 26 | 227 ± 58 | 366 ± 77 | 302 ± 69
Week 14 | 510 ± 156 | 388 ± 37 | 362 ± 57 | 328 ± 74 | 526 ± 159 | 281 ± 42
Sorbitol dehydrogenase (IU/L)
Day 4 | 14 ± 1 | 15 ± 1 | 16 ± 1 | 15 ± 1 | 16 ± 0 | 16 ± 1
Day 22 | 19 ± 2 | 17 ± 3 | 20 ± 2 | 20 ± 3 | 19 ± 3 | 18 ± 2
Week 14 | 35 ± 3 | 38 ± 1 | 41 ± 1 | 35 ± 3 | 34 ± 2 | 35 ± 2
Bile acids (µmol/L)
Day 4 | 26.4 ± 1.3 | 24.6 ± 0.8 | 27.3 ± 2.2 | 26.9 ± 1.6 | 40.3 ± 3.8** | 31.7 ± 2.8*
Day 22 | 24.0 ± 0.8 | 30.1 ± 1.5* | 27.0 ± 1.4 | 23.1 ± 1.1 | 29.1 ± 1.7 | 27.2 ± 1.0
Week 14 | 27.0 ± 1.7 | 34.3 ± 2.9 | 32.6 ± 1.4 | 34.8 ± 3.3 | 30.8 ± 1.5 | 36.4 ± 3.2*

* Significantly different (P ≤ 0.05) from the control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.

^b^ n = 9.

Table B-2 Hematology Data for Mice in the Three-month Drinking Water Study of o-Chloropyridine^a^

| 0 ppm | 10 ppm | 30 ppm | 100 ppm | 300 ppm | 1,000 ppm
Male
n | 10 | 10 | 10 | 10 | 10 | 10
Hematocrit (%) | 51.2 ± 0.4 | 51.4 ± 0.5 | 50.4 ± 0.7 | 50.2 ± 0.4 | 50.3 ± 0.6 | 50.5 ± 0.6
Hemoglobin (g/dL) | 16.4 ± 0.1 | 16.5 ± 0.1 | 16.1 ± 0.2 | 16.1 ± 0.1 | 16.2 ± 0.2 | 16.2 ± 0.2
Erythrocytes (10^6^/µL) | 10.63 ± 0.09 | 10.78 ± 0.10 | 10.46 ± 0.13 | 10.65 ± 0.07 | 10.67 ± 0.11 | 10.69 ± 0.08
Reticulocytes (10^6^/µL) | 0.25 ± 0.02 | 0.27 ± 0.02 | 0.29 ± 0.03 | 0.28 ± 0.02 | 0.28 ± 0.03 | 0.26 ± 0.03
Mean cell volume (fL) | 47.3 ± 0.3 | 47.3 ± 0.3 | 47.5 ± 0.2 | 46.8 ± 0.1 | 47.0 ± 0.4 | 46.7 ± 0.2
Mean cell hemoglobin (pg) | 15.2 ± 0.1 | 15.2 ± 0.1 | 15.2 ± 0.1 | 15.1 ± 0.1 | 15.1 ± 0.1 | 14.9 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 32.1 ± 0.2 | 32.1 ± 0.1 | 32.0 ± 0.1 | 32.2 ± 0.1 | 32.2 ± 0.1 | 32.1 ± 0.1
Platelets (10^3^/µL) | 585.6 ± 24.8 | 569.5 ± 15.9 | 580.9 ± 17.8 | 572.3 ± 17.3 | 549.7 ± 21.3 | 549.8 ± 17.9
Leukocytes (10^3^/µL) | 6.13 ± 0.35 | 6.39 ± 0.56 | 5.91 ± 0.34 | 6.07 ± 0.31 | 5.88 ± 0.28 | 5.95 ± 0.39
Segmented neutrophils (10^3^/µL) | 0.25 ± 0.02 | 0.28 ± 0.05 | 0.25 ± 0.03 | 0.28 ± 0.03 | 0.26 ± 0.03 | 0.27 ± 0.04
Lymphocytes (10^3^/µL) | 5.68 ± 0.33 | 5.86 ± 0.49 | 5.48 ± 0.30 | 5.56 ± 0.29 | 5.39 ± 0.29 | 5.44 ± 0.34
Monocytes (10^3^/µL) | 0.14 ± 0.01 | 0.15 ± 0.01 | 0.15 ± 0.02 | 0.14 ± 0.01 | 0.17 ± 0.05 | 0.14 ± 0.02
Basophils (10^3^/µL) | 0.031 ± 0.006 | 0.065 ± 0.025 | 0.033 ± 0.005 | 0.041 ± 0.005 | 0.034 ± 0.004 | 0.067 ± 0.023
Eosinophils (10^3^/µL) | 0.02 ± 0.00 | 0.04 ± 0.02 | 0.02 ± 0.00 | 0.03 ± 0.00 | 0.02 ± 0.00 | 0.04 ± 0.01
Female
n | 9 | 10 | 10 | 10 | 10 | 10
Hematocrit (%) | 50.9 ± 1.1 | 50.5 ± 0.7 | 48.9 ± 0.4 | 50.5 ± 0.4 | 48.8 ± 0.6 | 46.6 ± 0.4**
Hemoglobin (g/dL) | 16.2 ± 0.3 | 16.0 ± 0.2 | 15.7 ± 0.1 | 16.2 ± 0.1 | 15.7 ± 0.2 | 15.1 ± 0.1**
Erythrocytes (10^6^/µL) | 10.56 ± 0.20 | 10.42 ± 0.12 | 10.23 ± 0.09 | 10.54 ± 0.07 | 10.22 ± 0.13 | 9.96 ± 0.09**
Reticulocytes (10^6^/µL) | 0.40 ± 0.03 | 0.33 ± 0.03 | 0.32 ± 0.03 | 0.37 ± 0.03 | 0.37 ± 0.03 | 0.31 ± 0.03
Mean cell volume (fL) | 48.2 ± 0.2 | 48.2 ± 0.1 | 47.9 ± 0.2 | 47.9 ± 0.2 | 47.7 ± 0.2 | 46.9 ± 0.2**
Mean cell hemoglobin (pg) | 15.3 ± 0.1 | 15.3 ± 0.0 | 15.3 ± 0.1 | 15.4 ± 0.1 | 15.4 ± 0.0 | 15.2 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 31.8 ± 0.1 | 31.7 ± 0.1 | 32.0 ± 0.1 | 32.0 ± 0.1 | 32.2 ± 0.1 | 32.4 ± 0.1**
Platelets (10^3^/µL) | 461.3 ± 32.5 | 485.2 ± 28.8 | 518.3 ± 26.1 | 491.6 ± 24.8 | 552.1 ± 20.5* | 569.4 ± 23.2*
Leukocytes (10^3^/µL) | 4.18 ± 0.41 | 4.10 ± 0.24 | 4.07 ± 0.27 | 4.22 ± 0.31 | 4.16 ± 0.19 | 4.56 ± 0.27
Segmented neutrophils (10^3^/µL) | 0.21 ± 0.04 | 0.14 ± 0.02 | 0.21 ± 0.07 | 0.16 ± 0.02 | 0.13 ± 0.01 | 0.15 ± 0.02
Lymphocytes (10^3^/µL) | 3.80 ± 0.34 | 3.87 ± 0.23 | 3.73 ± 0.22 | 3.96 ± 0.29 | 3.93 ± 0.19 | 4.31 ± 0.27
Monocytes (10^3^/µL) | 0.08 ± 0.01 | 0.09 ± 0.01 | 0.09 ± 0.02 | 0.08 ± 0.01 | 0.08 ± 0.01 | 0.09 ± 0.01
Basophils (10^3^/µL) | 0.050 ± 0.017 | 0.019 ± 0.006 | 0.020 ± 0.007 | 0.024 ± 0.008 | 0.019 ± 0.007 | 0.011 ± 0.002
Eosinophils (10^3^/µL) | 0.03 ± 0.01 | 0.01 ± 0.00 | 0.01 ± 0.00 | 0.01 ± 0.01 | 0.01 ± 0.00 | 0.01 ± 0.00

* Significantly different (P ≤ 0.05) from the control group by Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.