# Appendix A Summary of Lesions in Rats and Mice

Table A-1 Summary of the Incidence of Nonneoplastic Lesions in Male Rats in the Three-month Drinking Water Study of o-Chloropyridine^a^

| 0 ppm | 10 ppm | 30 ppm | 100 ppm | 300 ppm | 1,000 ppm
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Survivors
Terminal sacrifice | 10 | 10 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (10) | (10) | (10) | (10) | (10)
Basophilic focus | 0 | 0 | 0 | 0 | 0 | 2 (20%)
Clear cell focus | 0 | 0 | 0 | 0 | 0 | 6 (60%)
Eosinophilic focus | 0 | 0 | 0 | 0 | 0 | 1 (10%)
Hepatodiaphragmatic nodule | 0 | 0 | 0 | 0 | 1 (10%) | 0
Bile duct, hyperplasia | 1 (10%) | 0 | 0 | 0 | 0 | 0
Hepatocyte, vacuolization cytoplasmic | 0 | 0 | 0 | 0 | 6 (60%) | 9 (90%)
Salivary glands | (9) | (0) | (0) | (0) | (0) | (10)
Parotid gland, basophilic focus | 2 (22%) | – | – | – | – | 5 (50%)
Cardiovascular System
Heart | (10) | (0) | (0) | (0) | (0) | (10)
Cardiomyopathy | 4 (40%) | – | – | – | – | 2 (20%)
Inflammation, chronic | 1 (10%) | – | – | – | – | 0
Endocrine System
Adrenal cortex | (10) | (0) | (0) | (0) | (0) | (10)
Zona fasciculata, vacuolization cytoplasmic | 9 (90%) | – | – | – | – | 5 (50%)
Zona reticularis, vacuolization cytoplasmic | 0 | – | – | – | – | 2 (20%)
Thyroid gland | (10) | (0) | (0) | (0) | (0) | (10)
Cyst | 1 (10%) | – | – | – | – | 0
Ectopic thymus | 1 (10%) | – | – | – | – | 1 (10%)
General Body System
None | – | – | – | – | – | –
Genital System
None | – | – | – | – | – | –
Hematopoietic System
Bone marrow | (10) | (10) | (10) | (10) | (10) | (10)
Hyperplasia | 1 (10%) | 0 | 2 (20%) | 1 (10%) | 9 (90%) | 6 (60%)
Lymph node, mesenteric | (10) | (0) | (0) | (0) | (0) | (10)
Sinus, histiocytosis | 0 | – | – | – | – | 2 (20%)
Spleen | (10) | (10) | (10) | (10) | (10) | (10)
Congestion | 4 (40%) | 1 (10%) | 2 (20%) | 0 | 7 (70%) | 10 (100%)
Hematopoietic cell proliferation | 4 (40%) | 8 (80%) | 6 (60%) | 6 (60%) | 10(100%) | 10(100%)
Pigmentation | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%)
Integumentary System
None | – | – | – | – | – | –
Musculoskeletal System
None | – | – | – | – | – | –
Nervous System
None | – | – | – | – | – | –
Respiratory System
Lung | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration cellular, mononuclear cell, focal | 1 (10%) | – | – | – | – | 0
Metaplasia, osseous | 2 (20%) | – | – | – | – | 0
Alveolus, hemorrhage, focal | 1 (10%) | – | – | – | – | 1 (10%)
Special Senses System
Eye | (10) | (0) | (0) | (0) | (0) | (10)
Posterior chamber, developmental malformation | 1 (10%) | – | – | – | – | 0
Urinary System
Kidney | (10) | (10) | (10) | (10) | (10) | (10)
Mineralization | 0 | 1 (10%) | 0 | 0 | 0 | 0
Nephropathy | 3 (30%) | 2 (20%) | 5 (50%) | 6 (60%) | 3 (30%) | 4 (40%)
Renal tubule, accumulation, hyaline droplet | 10 (100%) | 10 (100%) | 10 (100%) | 9 (90%) | 5 (50%) | 0

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.

Table A-2 Summary of the Incidence of Nonneoplastic Lesions in Female Rats in the Three-month Drinking Water Study of o-Chloropyridine^a^

| 0 ppm | 10 ppm | 30 ppm | 100 ppm | 300 ppm | 1,000 ppm
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Survivors
Terminal sacrifice | 10 | 10 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (10) | (10) | (10) | (10) | (10)
Clear cell focus | 0 | 0 | 0 | 0 | 0 | 2 (20%)
Hepatocyte, vacuolization cytoplasmic | 0 | 0 | 0 | 0 | 0 | 9 (90%)
Pancreas | (10) | (0) | (0) | (0) | (0) | (10)
Duct, hyperplasia | 1 (10%) | – | – | – | – | 0
Salivary glands | (10) | (0) | (0) | (0) | (0) | (10)
Parotid gland, basophilic focus | 3 (30%) | – | – | – | – | 2 (20%)
Cardiovascular System
Heart | (10) | (0) | (0) | (0) | (0) | (10)
Cardiomyopathy | 1 (10%) | – | – | – | – | 0
Epicardium, inflammation | 0 | – | – | – | – | 1 (10%)
Endocrine System
Adrenal cortex | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration cellular, mononuclear cell, focal | 0 | – | – | – | – | 1 (10%)
Pituitary gland | (9) | (0) | (0) | (0) | (0) | (10)
Pars distalis, cyst | 1 (11%) | – | – | – | – | 0
Thyroid gland | (10) | (0) | (0) | (0) | (0) | (10)
Cyst | 2 (20%) | – | – | – | – | 1 (10%)
Ectopic thymus | 1 (10%) | – | – | – | – | 0
General Body System
None | – | – | – | – | – | –
Genital System
Uterus | (10) | (0) | (0) | (0) | (0) | (10)
Dilatation | 1 (10%) | – | – | – | – | 3 (30%)
Hydrometra | 1 (10%) | – | – | – | – | 2 (20%)
Hematopoietic System
Bone marrow | (10) | (10) | (10) | (10) | (10) | (10)
Hyperplasia | 0 | 0 | 0 | 0 | 3 (30%) | 9 (90%)
Lymph node, mesenteric | (10) | (0) | (0) | (0) | (0) | (10)
Sinus, histiocytosis | 6 (60%) | – | – | – | – | 4 (40%)
Spleen | (10) | (10) | (10) | (10) | (10) | (10)
Congestion | 1 (10%) | 7 (70%) | 5 (50%) | 6 (60%) | 6 (60%) | 10 (100%)
Hematopoietic cell proliferation | 3 (30%) | 3 (30%) | 6 (60%) | 3 (30%) | 7 (70%) | 10 (100%)
Pigmentation | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%)
Thymus | (10) | (0) | (0) | (0) | (0) | (10)
Thymocyte, atrophy | 1 (10%) | – | – | – | – | 0
Integumentary System
None | – | – | – | – | – | –
Musculoskeletal System
None | – | – | – | – | – | –
Nervous System
None | – | – | – | – | – | –
Respiratory System
Lung | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration cellular, mononuclear cell, focal | 4 (40%) | – | – | – | – | 3 (30%)
Alveolus, hemorrhage, focal | 1 (10%) | – | – | – | – | 0
Special Senses System
Eye | (10) | (0) | (0) | (0) | (0) | (10)
Cornea, inflammation | 0 | – | – | – | – | 1 (10%)
Sclera, inflammation | 0 | – | – | – | – | 2 (20%)
Harderian gland | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration cellular developmental malformation | 0 | – | – | – | – | 1 (10%)
Urinary System
Kidney | (10) | (10) | (10) | (10) | (10) | (10)
Mineralization | 0 | 0 | 1 (10%) | 0 | 0 | 0
Nephropathy | 2 (20%) | 0 | 1 (10%) | 1 (10%) | 2 (20%) | 5 (50%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.

Table A-3 Summary of the Incidence of Neoplasms and Nonneoplastic Lesions in Male Mice in the Three-month Drinking Water Study of o-Chloropyridine^a^

| 0 ppm | 10 ppm | 30 ppm | 100 ppm | 300 ppm | 1,000 ppm
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Survivors
Terminal sacrifice | 10 | 10 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (10) | (10) | (10) | (10) | (10)
Infiltration cellular, mononuclear cell, focal | 1 (10%) | 0 | 1 (10%) | 0 | 1 (10%) | 1 (10%)
Necrosis, focal | 1 (10%) | 0 | 2 (20%) | 0 | 0 | 2 (20%)
Centrilobular, hepatocyte, hypertrophy | 0 | 0 | 0 | 1 (10%) | 6 (60%) | 9 (90%)
Stomach, glandular | (10) | (0) | (0) | (0) | (0) | (10)
Cyst | 0 | – | – | – | – | 1 (10%)
Cyst epithelial inclusion | 2 (20%) | – | – | – | – | 0
Cardiovascular System
None | – | – | – | – | – | –
Endocrine System
Adrenal cortex | (9) | (0) | (0) | (0) | (0) | (10)
Subcapsular, hyperplasia focal | 0 | – | – | – | – | 2 (20%)
Parathyroid gland | (7) | (0) | (0) | (0) | (0) | (7)
Cyst | 1 (14%) | – | – | – | – | 0
General Body System
None | – | – | – | – | – | –
Genital System
None | – | – | – | – | – | –
Hematopoietic System
Spleen | (10) | (0) | (0) | (0) | (0) | (10)
Hematopoietic cell proliferation | 10 (100%) | – | – | – | – | 10 (100%)
Integumentary System
None | – | – | – | – | – | –
Musculoskeletal System
None | – | – | – | – | – | –
Nervous System
None | – | – | – | – | – | –
Respiratory System
None | – | – | – | – | – | –
Special Senses System
None | – | – | – | – | – | –
Urinary System
Kidney | (10) | (10) | (10) | (10) | (10) | (10)
Mineralization | 0 | 0 | 0 | 0 | 2 (20%) | 0
Nephropathy | 0 | 0 | 0 | 0 | 0 | 1 (10%)
Interstitium, infiltration cellular, mononuclear cell | 0 | 0 | 1 (10%) | 0 | 0 | 1 (10%)
Renal tubule, adenoma | 0 | 0 | 1 (10%) | 0 | 0 | 0
Renal tubule, casts protein | 0 | 0 | 0 | 1 (10%) | 0 | 0
Renal tubule, vacuolization cytoplasmic | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.

Table A-4 Summary of the Incidence of Neoplasms and Nonneoplastic Lesions in Female Mice in the Three-month Drinking Water Study of o-Chloropyridine^a^

| 0 ppm | 10 ppm | 30 ppm | 100 ppm | 300 ppm | 1,000 ppm
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Early deaths
Natural death | 1 | – | – | – | – | –
Survivors
Terminal sacrifice | 9 | 10 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (10) | (10) | (10) | (10) | (10)
Infiltration cellular, mononuclear cell, focal | 0 | 1 (10%) | 1 (10%) | 0 | 1 (10%) | 0
Necrosis, focal | 0 | 0 | 0 | 0 | 0 | 1 (10%)
Centrilobular, hepatocyte, hypertrophy | 0 | 0 | 0 | 0 | 4 (40%) | 10 (100%)
Cardiovascular System
None | – | – | – | – | – | –
Endocrine System
Adrenal cortex | (10) | (0) | (0) | (0) | (0) | (10)
Subcapsular, hyperplasia, focal | 10 (100%) | – | – | – | – | 10 (100%)
General Body System
None | – | – | – | – | – | –
Genital System
Ovary | (10) | (0) | (0) | (0) | (0) | (10)
Teratoma, benign | 1 (10%) | – | – | – | – | 0
Uterus | (10) | (0) | (0) | (0) | (0) | (10)
Deciduoma, benign | 0 | – | – | – | – | 1 (10%)
Endometrium, hyperplasia cystic | 4 (40%) | – | – | – | – | 3 (30%)
Hematopoietic System
Spleen | (9) | (0) | (0) | (0) | (0) | (10)
Hematopoietic cell proliferation | 9 (100%) | – | – | – | – | 10 (100%)
Integumentary System
Skin | (10) | (0) | (0) | (0) | (0) | (10)
Dermis, inflammation | 1 (10%) | – | – | – | – | 0
Musculoskeletal System
None | – | – | – | – | – | –
Nervous System
None | – | – | – | – | – | –
Respiratory System | (10) | (0) | (0) | (0) | (0) | (10)
Lung
Hemorrhage, focal | 0 | – | – | – | – | 1 (10%)
Special Senses System
None | – | – | – | – | – | –
Urinary System
Kidney | (10) | (10) | (10) | (10) | (10) | (10)
Infiltration cellular, mononuclear cell | 0 | 0 | 1 (10%) | 0 | 0 | 0
Mineralization | 0 | 0 | 1 (10%) | 0 | 0 | 0
Nephropathy | 0 | 2 (20%) | 0 | 0 | 0 | 0
Interstitium, infiltration cellular, mononuclear cell | 1 (10%) | 0 | 0 | 0 | 0 | 0

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.