# Peer Review

The draft NTP Technical Report on the Toxicity Studies of α-Pinene (CAS No. 80-56-8) Administered by Inhalation to F344/N Rats and B6C3F1/N Mice was evaluated by the reviewers listed below. These reviewers served as independent scientists, not as representatives of any institution, company, or governmental agency. In this capacity, reviewers determined if the design and conditions of these NTP studies were appropriate and ensured that this NTP Toxicity Study Report presents the experimental results and conclusions fully and clearly.

## Peer Reviewers

- Terry Gordon, Ph.D.
  New York University School of Medicine
  Tuxedo, New York, USA
- Michael V. Pino, D.V.M., Ph.D.
  Veterinary Toxicologic Pathology and Preclinical Drug Development
  Albuquerque, New Mexico, USA