# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  C.V. Rider, Ph.D., Study Scientist
  R.A. Herbert, D.V.M., Ph.D., Study Pathologist
  C.R. Blystone, Ph.D.
  M.C. Cora, D.V.M., Ph.D.
  P.M. Foster, Ph.D.
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  G.E. Kissling, Ph.D.
  D.E. Malarkey, D.V.M., Ph.D.
  S.L. Smith-Roe, Ph.D.
  M.D. Stout, Ph.D.
  G.S. Travlos, D.V.M.
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
  K.L. Witt, M.S.
- Battelle Toxicology Northwest, Richland, Washington, USA
  Conducted studies and evaluated pathology findings
  J.A. Dill, Ph.D., Principal Investigator
  S.L. Grumbein, D.V.M., Ph.D.
  S.J. Harbo, D.V.M.
  B.K. Hayden
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Conducted pathology review
  C.D. Houle, D.V.M.
  R.A. Miller, D.V.M., Ph.D.
- Pathology Associates, a Division of Charles River Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Coordinated NTP Pathology Peer Review (June 30, 2006)
  W.G. Lieuallen, D.V.M., Ph.D.
- Gene Logic Laboratories, Inc., Gaithersburg, Maryland, USA
  Provided SMVCE analysis
  B.J.T. Muir, Ph.D., Principal Investigator
  B. Atkinson, M.Sc.
  Y. Wang, M.S.