# References

1 Hazardous Substances Data Bank (HSDB). National Institutes for Occupational Safety and Health (NIOSH); 2010. https://www.nlm.nih.gov/databases/download/hsdb.html.
2 Persson M, Sjödin K, Borg-Karlson A-K, Norin T, Ekberg I. Relative amounts and enantiomeric compositions of monoterpene hydrocarbons in xylem and needles of Picea abies. Phytochemistry. 1996; 42(5):1289–1297.10.1016/0031-9422(96)00119-7
3 Sjödin K, Persson M, Borg-Karlson A-K, Norin T. Enantiomeric compositions of monoterpene hydrocarbons in different tissues of four individuals of Pinus sylvestris. Phytochemistry. 1996; 41(2):439–445.10.1016/0031-9422(95)00652-4 8688173
4 Wibe A, Borg-Karlson A-K, Persson M, Norin T, Mustaparta H. Enantiomeric composition of monoterpene hydrocarbons in some conifers and receptor neuron discrimination of α-pinene and limonene enantiomers in the pine weevil, Hylobius abietis. J Chem Ecol. 1998; 24(2):273–287.10.1023/A:1022580308414
5 Phillips MA, Savage TJ, Croteau R. Monoterpene synthases of loblolly pine (Pinus taeda) produce pinene isomers and enantiomers. Arch Biochem Biophys. 1999; 372(1):197–204. 10.1006/abbi.1999.1467 10562434
6 de Carvalho CC, da Fonseca MM. Biotransformation of terpenes. Biotechnol Adv. 2006; 24:134–142. 10.1016/j.biotechadv.2005.08.004 16169182
7 O’Neil M, editor. The Merck Index. Whitehouse Station, NJ: Merck; 2006.
8 Cal K. Aqueous solubility of liquid monoterpenes at 293 K and relationship with calculated log P value. Yakugaku Zasshi. 2006; 126(4):307–309. 10.1248/yakushi.126.307 16596022
9 McGarvey DJ, Croteau R. Terpenoid metabolism. Plant Cell. 1995; 7(7):1015. 10.1105/tpc.7.7.1015 7640522
10 Atkinson R, Arey J. Gas-phase tropospheric chemistry of biogenic volatile organic compounds: A review. Atmos Environ. 2003; 37:197–219.10.1016/S1352-2310(03)00391-1
11 National Institute for Occupational Safety and Health (NIOSH). NIOSH pocket guide to chemical hazards. Atlanta, GA: Department of Health and Human Services, Centers for Disease Control and Prevention, National Institute for Occupational Safety and Health; 2010. https://www.cdc.gov/niosh/docs/2010-168c
12 American Conference of Governmental Industrial Hygienists (ACGIH). 2014 TLVs and BEIs. Threshold limit values for chemical substances and physical agents and biological exposure indices. Cincinnati, OH; 2012.
13 Demers PA, Teschke K, Davies HW, Kennedy SM, Leung V. Exposure to dust, resin acids, and monoterpenes in softwood lumber mills. AIHAJ. 2000; 61(4):521-528. 10.1202/0002-8894(2000)061<0521:ETDRAA>2.0.CO;2
14 Fransman W, McLean D, Douwes J, Demers PA, Leung V, Pearce N. Respiratory symptoms and occupational exposures in New Zealand plywood mill workers. Ann Occup Hyg. 2003; 47(4):287–295. 12765869
15 Rosenberg C, Liukkonen T, Kallas‐Tarpila T, Ruonakangas A, Ranta R, Nurminen M, Welling I, Jäppinen P. Monoterpene and wood dust exposures: Work‐related symptoms among Finnish sawmill workers. Am J Ind Med. 2002; 41(1):38–53. 10.1002/ajim.10033 11757054
16 Eriksson KA, Levin JO, Sandström T, Lindström-Espeling K, Lindén G, Stjernberg NL. Terpene exposure and respiratory effects among workers in Swedish joinery shops. Scand J Work Environ Health. 1997; 23(2):114–120. 10.5271/sjweh.188 9167234
17 Edman K, Löfstedt H, Berg P, Eriksson K, Axelsson S, Bryngelsson I, Fedeli C. Exposure assessment to α-and β-pinene, Δ3-carene and wood dust in industrial production of wood pellets. Ann Occup Hyg. 2003; 47(3):219–226. 12639835
18 Hedenstierna G, Alexandersson R, Wimander K, Rosen G. Exposure to terpenes: Effects on pulmonary function. Int Arch Occup Environ Health. 1983; 51(3):191–198. 10.1007/BF00377751 6852927
19 Van Durme GP, McNamara BF, McGinley CM. Bench-scale removal of odor and volatile organic compounds at a composting facility. Water Environ Res. 1992; 64(1):19–27.10.2175/WER.64.1.4
20 Nazaroff WW, Weschler CJ. Cleaning products and air fresheners: Exposure to primary and secondary air pollutants. Atmos Environ. 2004; 38(18):2841–2865.10.1016/j.atmosenv.2004.02.040
21 Rastogi SC, Heydorn S, Johansen J, Basketter D. Fragrance chemicals in domestic and occupational products. Contact Dermatitis. 2001; 45(4):221–225. 10.1034/j.1600-0536.2001.450406.x 11683833
22 Colombo A, De Bortoli M, Knöppel H, Schauenburg H, Vissers H. Small chamber tests and headspace analysis of volatile organic compounds emitted from household products. Indoor Air. 1991; 1(1):13–21.10.1111/j.1600-0668.1991.02-11.x
23 Jia C, Batterman S, Godwin C. VOCs in industrial, urban and suburban neighborhoods, Part 1: Indoor and outdoor concentrations, variation, and risk drivers. Atmos Environ. 2008; 42(9):2083–2100.10.1016/j.atmosenv.2007.11.055
24 Falk AA, Hagberg MT, Löf AE, Wigaeus-Hjelm EM, Zhiping W. Uptake, distribution and elimination of α-pinene in man after exposure by inhalation. Scand J Work Environ Health. 1990; 16(5):372–378. 10.5271/sjweh.1771 2255878
25 Filipsson AF. Short term inhalation exposure to turpentine: Toxicokinetics and acute effects in men. Occup Environ Med. 1996; 53(2):100–105. 10.1136/oem.53.2.100 8777445
26 Southwell IA, Flynn TM, Degabriele R. Metabolism of α-and β-pinene, β-cymene and 1, 8-cineole in the brushtail possum, Trichosurus vulpecula. Xenobiotica. 1980; 10(1):17–23. 10.3109/00498258009033726 7385912
27 Ishida T, Asakawa Y, Takemoto T, Aratani T. Terpenoids biotransformation in mammals III: Biotransformation of α‐pinene, β‐pinene, pinane, 3‐carene, carane, myrcene, and p‐cymene in rabbits. J Pharm Sci. 1981; 70(4):406–415. 10.1002/jps.2600700417 7229954
28 Levin J-O, Eriksson K, Falk A, Löf A. Renal elimination of verbenols in man following experimental α-pinene inhalation exposure. Int Arch Occup Environ Health. 1992; 63(8):571–573. 10.1007/BF00386348 1587632
29 Eriksson K, Levin J-O. Identification of cis-and trans-verbenol in human urine after occupational exposure to terpenes. Int Arch Occup Environ Health. 1990; 62(5):379–383. 10.1007/BF00381368 2228258
30 Köppel C, Tenczer J, Tönnesmann U, Schirop T, Ibe K. Acute poisoning with pine oil—Metabolism of monoterpenes. Arch Toxicol. 1981; 49(1):73–78. 10.1007/BF00352074 7325802
31 Johard U, Larsson K, Löf A, Eklund A. Controlled short‐time terpene exposure induces an increase of the macrophages and the mast cells in bronchoalveolar lavage fluid. Am J Ind Med. 1993; 23(5):793–799. 10.1002/ajim.4700230512 8506856
32 Kasanen J-P, Pasanen A-L, Pasanen P, Liesivuori J, Kosma V-M, Alarie Y. Stereospecificity of the sensory irritation receptor for nonreactive chemicals illustrated by pinene enantiomers. Arch Toxicol. 1998; 72(8):514–523. 10.1007/s002040050536 9765067
33 Wei Q, Harada K, Ohmori S, Minamoto K, Wei C, Ueda A. Toxicity study of the volatile constituents of Myoga utilizing acute dermal irritation assays and the Guinea-pig Maximization test. J Occup Health. 2006; 48(6):480–486. 10.1539/joh.48.480 17179641
34 Kauppinen TP, Partanen TJ, Hernberg SG, Nickels JI, Luukkonen RA, Hakulinen TR, Pukkala EI. Chemical exposures and respiratory cancer among Finnish woodworkers. Br J Ind Med. 1993; 50(2):143–148. 10.1136/oem.50.2.143 8435346
35 De Roos AJ, Olshan AF, Teschke K, Poole C, Savitz DA, Blatt J, Bondy ML, Pollock BH. Parental occupational exposures to chemicals and incidence of neuroblastoma in offspring. Am J Epidemiol. 2001; 154(2):106–114. 10.1093/aje/154.2.106 11447042
36 Florin I, Rutberg L, Curvall M, Enzell CR. Screening of tobacco smoke constituents for mutagenicity using the Ames’ test. Toxicology. 1980; 15(3):219–232. 10.1016/0300-483X(80)90055-4 7008261
37 Connor TH, Theiss JC, Hanna HA, Monteith DK, Matney TS. Genotoxicity of organic chemicals frequently found in the air of mobile homes. Toxicol Lett. 1985; 25(1):33–40. 10.1016/0378-4274(85)90097-9 3887653
38 Gomes-Carneiro MR, Viana ME, Felzenszwalb I, Paumgartten FJ. Evaluation of β-myrcene, α-terpinene and (+)-and (−)-α-pinene in the Salmonella/microsome assay. Food Chem Toxicol. 2005; 43(2):247–252. 10.1016/j.fct.2004.09.011 15621337
39 Gminski R, Tang T, Mersch-Sundermann V. Cytotoxicity and genotoxicity in human lung epithelial A549 cells caused by airborne volatile organic compounds emitted from pine wood and oriented strand boards. Toxicol Lett. 2010; 196(1):33–41. 10.1016/j.toxlet.2010.03.015 20362040
40 Catanzaro I, Caradonna F, Barbata G, Saverini M, Mauro M, Sciandrello G. Genomic instability induced by α-pinene in Chinese hamster cell line. Mutagenesis. 2012; 27(4):463–469. 10.1093/mutage/ges005 22379123
41 Chapman EM. Observations on the effect of paint on the kidneys with particular reference to the role of turpentine. J Ind Hyg Toxicol. 1941; 23:277–289.
42 Brecher G, Schneiderman M. A time-saving device for the counting of reticulocytes. Am J Clin Pathol. 1950; 20(11_ts):2079-2084. 10.1093/ajcp/20.11_ts.1079
43 Maronpot RR, Boorman GA. Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982; 10(2):71–78. 10.1177/019262338201000210 28094716
44 Boorman GA, Montgomery CA Jr, Eustis SL, Wolfe MJ, McConnell EE, Hardisty JF. Quality assurance in pathology for rodent carcinogenicity studies. In: Milman HA, Weisburger EK, editors. Handbook of Carcinogen Testing. Park Ridge, NJ: Noyes Publications; 1985. p. 345–357.
45 Gart JJ, Chu KC, Tarone RE. Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979; 62(4):957–974. 285297
46 Dunnett CW. A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121.10.1080/01621459.1955.10501294
47 Williams DA. A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971; 27(1):103–117. 10.2307/2528930 5547548
48 Williams DA. The comparison of several dose levels with a zero dose control. Biometrics. 1972; 28(2):519–531. 10.2307/2556164 5037867
49 Shirley E. A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977; 33(2):386–389. 10.2307/2529789 884197
50 Williams DA. A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986; 42(1):183–186. 10.2307/2531254 3719054
51 Dunn OJ. Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252.10.1080/00401706.1964.10490181
52 Jonckheere AR. A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41:133–145.10.1093/biomet/41.1-2.133
53 Dixon W, Massey F. Introduction to statistical analysis. New York, NY: McGraw Hill Book Company Inc; 1957.10.2307/2332898
54 Girard DM, Sager DB. The use of Markov chains to detect subtle variation in reproductive cycling. Biometrics. 1987; 43(1):225–234. 10.2307/2531963 3567307
55 Code of Federal Regulations (CFR). 21:Part 58.
56 Zeiger E, Anderson B, Haworth S, Lawlor T, Mortelmans K. Salmonella mutagenicity tests. 5. Results from the testing of 311 chemicals. Environ Mol Mutag. 1992; 19:2-141. 10.1002/em.2850190603
57 MacGregor JT, Wehr CM, Henika PR, Shelby MD. The in vivo erythrocyte micronucleus test: Measurement at steady state increases assay efficiency and permits integration with toxicity studies. Fundam Appl Toxicol. 1990; 14(3):513–522. 10.1016/0272-0590(90)90255-I 2111256
58 Occupational Safety and Health Administration (OSHA). Occupational safety and health guideline for turpentine. 2013. https://www.osha.gov/SLTC/healthguidelines/turpentine/recognition.html [Accessed: February 13, 2013]
59 Swenberg JA. Alpha 2u-globulin nephropathy: Review of the cellular and molecular mechanisms involved and their implications for human risk assessment. Environ Health Perspect. 1993; 101 Suppl 6:39. 10.1289/ehp.93101s639 7517351
60 Doi AM, Hill G, Seely J, Hailey JR, Kissling G, Bucher JR. α2u-Globulin nephropathy and renal tumors in National Toxicology Program studies. Toxicol Pathol. 2007; 35(4):533–540. 10.1080/01926230701338941 17562486
61 United States Environmental Protection Agency (USEPA). Alpha 2u-globulin: Association with chemically induced renal toxicity and neoplasia in the male rat. Washington, DC: U.S. Environmental Protection Agency, prepared for the Risk Assessment Forum; 1991. https://www.epa.gov/raf/publications/alpha2u-globulin.htm.
62 International Agency for Research on Cancer (IARC). Species differences in thyroid, kidney and urinary bladder carcinogenesis. Lyon, France; 1999. IARC Scientific Publication No. 147.
63 National Toxicology Program (NTP). Technical report on the toxicology and carcinogenesis studies of t butyl alcohol (CAS No. 75-65-0) in F344/N rats and B6C3F1 mice (drinking water studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1995. Technical Report Series No. 436. NIH Publication No. 95-3167.
64 National Toxicology Program (NTP). Technical report on the toxicology and carcinogenesis studies of 2,2 bis(bromomethyl)-1,3-propanediol (FR-1138®) (CAS No. 3296-90-0) in F344/N rats and B6C3F1 mice (feed studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1996. Technical Report Series No. 452. NIH Publication No. 96-3368.
65 National Toxicology Program (NTP). Technical report on the toxicity studies of methyl ethyl ketoxime (CAS No. 96-29-7) administered in drinking water to F344/N rats and B6C3F1 mice. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1999. Toxicity Report Series No. 51. NIH Publication No. 99-3947.
66 Koss L, Hoda R. Tumors and related conditions of the bladder and lower urinary tract. In: Koss L, Hoda R, editors. Koss’s Cytology of the Urinary Tract with Histopathologic Correlations. New York, NY: Springer; 2012. p. 73–108.10.1007/978-1-4614-2056-9_6
67 Sakata T, Masui T, John MS, Cohen SM. Uracil-induced calculi and proliferative lesions of the mouse urinary bladder. Carcinogenesis. 1988; 9(7):1271–1276. 10.1093/carcin/9.7.1271 3383344
68 Shirai T, Tagawa Y, Fukushima S, Imaida K, Ito N. Strong promoting activity of reversible uracil-induced urolithiasis on urinary bladder carcinogenesis in rats initiated with N-butyl-N-(4-hydroxybutyl) nitrosamine. Cancer Res. 1987; 47(24 Part 1):6726–6730. 3677102
69 Fukushima S, Tanaka H, Asakawa E, Kagawa M, Yamamoto A, Shirai T. Carcinogenicity of uracil, a nongenotoxic chemical, in rats and mice and its rationale. Cancer Res. 1992; 52(7):1675–1680. 1551098
70 Ogawa K, Uzvolgyi É, St. John MK, De Oliveira ML, Arnold L, Cohen SM. Frequent p53 mutations and occasional loss of chromosome 4 in invasive bladder carcinoma induced by N‐butyl‐N‐(4‐hydroxybutyl) nitrosamine in B6D2F1 mice. Mol Carcinog. 1998; 21(1):70-79. 10.1002/(SICI)1098-2744(199801)21:1<70:AID-MC9>3.0.CO;2-T
71 Liang J-H, Sankai T, Yoshida T, Yoshikawa Y. Comparison of the effects of two fixatives for immunolocalization of testosterone in the testes of the Cynomolgus monkey, mouse and rat. Exp Anim. 2000; 49(4):301–304. 10.1538/expanim.49.301 11109557
72 Latendresse JR, Warbrittion AR, Jonassen H, Creasy DM. Fixation of testes and eyes using a modified Davidson’s fluid: Comparison with Bouin’s fluid and conventional Davidson’s fluid. Toxicol Pathol. 2002; 30(4):524–533. 10.1080/01926230290105721 12187944
73 Pap A, Szarvas F. Effect of alpha-pinene on the mixed function microsomal oxidase system in the rat. Acta Med Acad Sci Hung. 1976; 33(4):379–385. 1032243
74 Austin CA, Shephard EA, Pike SF, Rabin BR, Phillips IR. The effect of terpenoid compounds on cytochrome P-450 levels in rat liver. Biochem Pharmacol. 1988; 37(11):2223–2229. 10.1016/0006-2952(88)90585-0 3377821
75 Hiroi T, Miyazaki Y, Kobayashi Y, Imaoka S, Funae Y. Induction of hepatic P450s in rat by essential wood and leaf oils. Xenobiotica. 1995; 25(5):457–467. 10.3109/00498259509061865 7571719
76 Lamb JG, Marick P, Sorensen J, Haley S, Dearing MD. Liver biotransforming enzymes in woodrats Neotoma stephensi (Muridae). Comp Biochem Physiol C Toxicol Pharmacol. 2004; 138(2):195–201. 10.1016/j.cca.2004.07.003 15450867
77 National Toxicology Program (NTP). Technical report on the toxicology and carcinogenesis studies of β myrcene (CAS No. 123-35-3) in F344/N rats and B6C3F1 mice (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2010. Technical Report Series No. 557. NIH Publication No. 11-5898.
78 National Toxicology Program (NTP). Technical report on the toxicology and carcinogenesis studies of d limonene (CAS No. 5989-27-5) in F344/N rats and B6C3F1 mice (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1990. Technical Report Series No. 347. NIH Publication No. 90-2802.
79 National Toxicology Program (NTP). Technical report on the toxicology and carcinogenesis studies of citral (microencapsulated) (CAS No. 5392-40-5) in F344/N rats and B6C3F1 mice (feed studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2003. Technical Report Series No. 505. NIH Publication No. 03-4439.
80 National Toxicology Program (NTP). Technical report on the carcinogenesis studies of food grade geranyl acetate (71% geranyl acetate, 29% citronellyl acetate) (CAS No. 105-87-3) in F344/N rats and B6C3F1 mice (gavage study). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1987. Technical Report Series No. 252. NIH Publication No. 88-2508.
81 National Toxicology Program (NTP). Technical report on the toxicology and carcinogenesis studies of α,β thujone (CAS No. 76231-76-0) in F344/N rats and B6C3F1 mice (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2011. Technical Report Series No. 570. NIH Publication No. 12-5912.
82 The Aldrich library of FT-IR spectra. Milwaukee, WI: Aldrich Chemical Company Inc.; 1997.
83 Pouchert C, Behnke J, editors. The Aldrich library of 13C and 1H FT-NMR spectra. Milwaukee, WI: Aldrich Chemical Company, Inc; 1993.