# Errata

An error was identified in the NTP Toxicity Report on α-pinene (TOX 81). Introduction text on page 2 in the Product, Use, and Human Exposure section was updated to accurately reflect indoor exposure levels reported in a study conducted in homes in Michigan. [24 August 2020]