# Discussion

α-Pinene is the primary constituent of turpentine: an oleoresin extracted from coniferous trees, especially of the genus Pinus. α-Pinene belongs to a class of chemicals known as monoterpenes, which contain two isoprene units and include other members that are also present in turpentine: β-pinene, ∆^3^-carene, and d-limonene. In addition to its presence in turpentine, which is used primarily as a solvent, α-pinene is used as a flavor enhancer in foods or as a fragrance ingredient in personal care products, household cleaners, or air fresheners. Exposure to α-pinene can occur occupationally (e.g., wood processing industry, painting)^13,15^ or through the use of household goods.^21^ Workplace exposure limits for α-pinene include a legal permissible exposure limit (PEL) and recommended airborne exposure limit (REL) of 100 ppm (as turpentine)^11^ and a threshold limit value (TLV) of 20 ppm averaged over an 8-hour workshift.^12^ Despite widespread exposure potential, there are very little data available for characterizing the toxicity or carcinogenicity of this compound. The present report describes the 2-week and 3-month toxicity studies of α-pinene administered to F344/N rats and B6C3F1/N mice by inhalation. The toxicity targets of α-pinene were generally consistent across species and included the liver, urinary system (kidneys in rats and bladder in mice), and cauda epididymal sperm.

Exposure concentrations for the 2-week studies with α-pinene were selected based on early studies with turpentine in which rats were exposed in a chamber to concentrations of turpentine roughly estimated at 5,000 to 10,000 mg/m^3^ or 897 to 1,795 ppm.^41^ In the 2-week studies with α-pinene, the two highest exposure concentrations (800 and 1,600 ppm) were overtly toxic to both rats and mice, resulting in clinical findings of toxicity (e.g., ataxia, tremors, abnormal breathing) and death. In the remaining exposed groups, there was evidence of a general increase in absolute and/or relative liver and kidney weights compared to chamber control rats and mice of both sexes. The greatest weight changes (approximately 17% increases in relative liver weight in the 400 ppm male rats and mice) were not considered to be life threatening. Therefore, 400 ppm was selected as the high concentration for the 3-month studies in rats and mice.

In the 3-month studies, female rats appeared to be more sensitive to α-pinene than male rats or male or female mice. The high exposure concentration of 400 ppm resulted in the death of 60% of female rats and lower body weights in surviving females compared to the chamber controls but was not overtly toxic to male rats, male mice, or female mice. Additionally, an exposure concentration-dependent increase in relative heart weight at 100 ppm or greater was observed only in female rats; however, there were no accompanying histopathologic lesions in the heart.

While there are no data characterizing the effects of α-pinene on the urinary system of rodents or humans, the association between exposure to turpentine and acute renal injury in humans has long been recognized.^41^ The Occupational Safety and Health Administration^58^ lists toxic glomerulonephritis and bladder irritation with hematuria, albuminuria, oliguria, and dysuria among human effects associated with overexposure to turpentine vapors. However, the chronic effects of turpentine, or α-pinene, to the urinary system remain unknown. In the only identified study on the subject, Chapman^41^ exposed rats to turpentine vapors at exposure concentrations roughly estimated by the National Toxicology Program (NTP) at 5,000 to 10,000 mg/m^3^ or 897 to 1,795 ppm for periods ranging from 6.5 hours on a single day to 293 hours over the course of a year and did not find any histopathologic signs of renal injury.

In the current studies, there were multiple indications of urinary system injury following α-pinene exposure. In the 2-week and 3-month studies, relative kidney weights were increased in an exposure concentration-dependent manner in male and female rats. In male rats, exposure to α-pinene was associated with increases in the incidence and severity of hyaline droplet accumulation within the epithelial cells of the P2 segment of the renal tubule. In addition, prominent granular casts were observed in the lumens of the renal tubules along the corticomedullary junction. These casts are an indication of previous injury and death of the renal tubule epithelium with accumulation of the cellular debris (casts) in the tubules. There was also evidence of exacerbation of the chronic progressive nephropathy that is a common spontaneous change in the kidneys of male rats as evidenced by an exposure concentration-related increase in the severity of this lesion. Nephropathy was characterized by randomly distributed multifocal clusters of regenerating tubules within the parenchyma of the kidney. The presence of these nonneoplastic lesions in the kidney is suggestive of α2μ-globulin nephropathy, a renal syndrome that occurs in male but not female F334/N rats and that has been linked to the development of renal tubule neoplasms.^59^ This syndrome has been produced by structurally diverse chemicals and is thought to be secondary to toxicity caused by accumulation of hyaline droplets within the renal tubule epithelial cells. The kidney lesions observed in the current study are consistent with those observed in 90-day studies of d-limonene, decalin, and propylene glycol mono-t-butyl ether for which the mechanism of renal tumor induction in 2-year studies was considered to be related to α2μ-globulin nephropathy.^60^ The lesions meet some of the criteria used by the United States Environmental Protection Agency^61^ and the International Agency for Research on Cancer^62^ for induction of renal tumors by this mechanism. However, it should be noted that measures of α2μ-globulin and cell proliferation, which are also criteria used by these agencies, were not performed in the current studies. While it is possible that the observed kidney lesions are secondary to α2μ-globulin nephropathy, the increases in kidney weights in both male and female rats suggest that another independent mechanism of toxicity may have played a role in the lesion development.

Further evidence of α-pinene targeting the urinary system was found in the 3-month study of male and female mice. The primary effect in mice caused by exposure to α-pinene was an increased incidence of transitional epithelium hyperplasia of the urinary bladder in males and females exposed to 100 ppm or more, the severity of which increased with increasing exposure concentration. This finding is relatively rare among subchronic mouse studies at the NTP, with few test articles identified (e.g., 2,2-bis(bromomethyl)-1,3-propanediol, methyl ethyl ketoxime, t-butyl alcohol) that elicited treatment-dependent increased incidences of urinary bladder transitional epithelium hyperplasia in mice following 13 weeks of exposure.^63-65^ Transitional epithelium hyperplasia in the urinary bladder can be either reparative (e.g., regenerative or reactive) or preneoplastic, but there are no histologic features that can be used to reliably distinguish between the two etiologies.^66^ Reparative hyperplasia is a common secondary response to inflammation and/or necrosis in the urinary bladder and may also occur when urinary calculi (solid particles or “stones”) are present. Preneoplastic hyperplasia of the transitional epithelium is considered a component lesion in the continuum to neoplasia in the urinary bladder, and when present, cellular atypia or atypical growth patterns may provide plausible evidence that the hyperplasia is preneoplastic. Specific histopathologic indicators of either type of hyperplasia (e.g., calculi for reparative, cellular atypia for preneoplastic) were not evident in male or female mice from the current study; therefore, the neoplastic potential of the transitional epithelium hyperplasia of the urinary bladder that did occur is uncertain. Importantly, hyperplasia is often noted in studies of urinary bladder carcinogens in mice. In one class of urinary bladder carcinogens, irritation from chemically induced foreign bodies in the urinary bladder leads to reparative hyperplasia and eventually cancer, exemplified by uracil,^67^ which is a nongenotoxic urinary bladder carcinogen with promoting potential.^68,69^ A second class of urinary bladder carcinogens in mice, including N-butyl-N-(4-hydroxybutyl)nitrosamine^70^ elicit DNA damage, and induce preneoplastic hyperplasia followed by tumor production. Therefore, it is plausible that a chemical or compound that is carcinogenic to the transitional epithelium of the urinary bladder is likely to cause an increased incidence of transitional epithelium hyperplasia as a precursor to neoplasia.

In addition to the urinary system, the male reproductive system appeared to be a target of α-pinene toxicity, with more pronounced effects in mice than in rats. In male rats, absolute sperm per cauda decreased by approximately 20% at the two highest exposure concentrations compared to chamber controls. There was an accompanying minor decrease in epididymal weights that did not reach significance. Therefore, the possibility that the change in absolute sperm per cauda was due to a decrease in epididymal weight cannot be ruled out. In male mice, sperm per mg cauda decreased by 24% and 37% in the 200 and 400 ppm groups, respectively. Although histopathologic changes in the epididymides or testes would be expected to accompany decreases of this magnitude, artifacts in the male reproductive tract tissues resulting from formalin fixation precluded a definitive assessment of those tissues.^71,72^ Since the α-pinene studies were conducted, the NTP has implemented the use of Davidson’s fluid for fixation of male reproductive tissue, which has greatly improved resolution. Further studies on the effects of α-pinene on reproductive function are warranted. Under the conditions of the 3-month studies in rats and mice, there was no evidence of female reproductive toxicity.

Finally, α-pinene elicited relatively weak signals of potential toxicity in the liver of mice and rats. Liver weights were increased in exposed animals of both sexes and species. In female rats, a significant increase in relative liver weight was observed at the lowest exposure tested (25 ppm). Increased liver weight is a common finding in toxicity studies and can be associated with induction of liver metabolizing enzymes. α-Pinene has been shown to increase both phase I and phase II metabolizing enzymes in vitro and in vivo.^73-76^

There is limited overlap in target sites across monoterpene class members that have been tested by the NTP, including β-myrcene,^77^ d-limonene,^78^ citral,^79^ geranyl acetate^80^ and α,β-thujone.^81^ α-Pinene, citral, and d-limonene elicited kidney lesions in male rats suggestive of an α2μ-globulin mechanism of toxicity (e.g., granular casts and accumulation of hyaline droplets); however, there does not appear to be a typical monoterpene toxicity profile. For example, α-pinene was the only monoterpene tested that induced hyperplasia of the urinary bladder in mice or decreased cauda epididymal sperm in male mice and rats, while many of the other monoterpenes did not elicit specific histopathologic changes in mice in the 3-month studies, but had unique targets in male and female rats, including the nose (β-myrcene), forestomach and bone marrow (citral), and brain (α,β-thujone).

In studies performed by the NTP, α-pinene was not mutagenic in vitro or in vivo. These results are consistent with the majority of previous assessments of genotoxicity of α-pinene.^36-39^ Additionally, many other structurally related monoterpenes have been found to be nongenotoxic, regardless of their carcinogenicity in vivo.^77-81^ In contrast, increased frequencies of chromosomal aberrations and micronuclei (some of which contained kinetochores) were observed in V79 Chinese hamster cells exposed to α-pinene.^40^ These clastogenic and aneugenic effects were accompanied by increased formation of reactive oxygen species and disruption of the mitotic spindle.^40^ The in vivo micronucleus test is only sensitive to test articles (or their reactive metabolites) that reach the bone marrow. In the micronucleus studies conducted by NTP (Table B-2), α-pinene did not alter the percentage of polychromatic erythrocytes in peripheral blood of mice and did not affect the hematopoietic system in rats or mice (Table A-1 through Table A-4). These observations suggest that α-pinene either was not toxic to bone marrow or did not reach the bone marrow compartment. Given the findings by Catanzaro et al.^40^ and the observation that monoterpenes structurally related to α-pinene are carcinogenic, additional testing using the comet assay to assess the potential for α-pinene to induce DNA damage in cells of the lung (site of contact), liver, kidney, or urinary bladder (sites of lesions in the 3-month studies) may be informative.

Under the conditions of the 3-month inhalation studies, there were treatment-related lesions in male and female rats and mice. The major targets from α-pinene exposure in rats and mice included the liver, urinary system (kidney of rats and urinary bladder of mice), and cauda epididymal sperm. The most sensitive measures of α-pinene exposure in each species and sex were increased incidences of kidney lesions in male rats [lowest-observed-effect level (LOEL) = 25 ppm], increased relative liver weights in female rats (LOEL = 25 ppm) without accompanying histopathologic changes, decreased sperm per cauda and increased incidences of transitional epithelium hyperplasia of the urinary bladder in male mice (LOEL = 100 ppm), and increased incidences of transitional epithelium hyperplasia of the urinary bladder in female mice (LOEL = 100 ppm).