# Results

## Rats

### Two-week Study

All rats exposed to 1,600 ppm were found dead by day 2 (Table 2). All rats exposed to 800 ppm were found dead by day 16. Final mean body weights of all exposed rats that survived to the end of the study were similar to those of the chamber controls; the mean body weight gain of 400 ppm females was significantly less than that of the chamber control group (Table 2). Abnormal breathing, ataxia, lethargy, and nasal/eye discharge occurred in one 1,600 ppm male. In rats exposed to 800 ppm, nasal/eye discharge was observed in two males and five females, ataxia was observed in two males and two females, and tremors and abnormal breathing were observed in one male. Nasal/eye discharge and tremors were observed in three females exposed to 400 ppm.

Table 2 Survival and Body Weights of Rats in the Two-week Inhalation Study of α-Pinene^a^

Concentration (ppm) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 5/5 | 101 ± 3 | 172 ± 3 | 71 ± 4
100 | 5/5 | 101 ± 3 | 171 ± 2 | 70 ± 1 | 99
200 | 5/5 | 102 ± 3 | 173 ± 7 | 71 ± 5 | 100
400 | 5/5 | 100 ± 3 | 176 ± 4 | 75 ± 2 | 102
800 | 0/5^c^ | 101 ± 3 | – | – | –
1,600 | 0/5^d^ | 102 ± 4 | – | – | –
Female
0 | 5/5 | 91 ± 2 | 125 ± 3 | 34 ± 2
100 | 5/5 | 90 ± 2 | 130 ± 3 | 40 ± 2 | 104
200 | 5/5 | 91 ± 2 | 129 ± 2 | 38 ± 2 | 103
400 | 5/5 | 92 ± 1 | 118 ± 2 | 26 ± 2* | 94
800 | 0/5^e^ | 92 ± 2 | – | – | –
1,600 | 0/5^f^ | 91 ± 1 | – | – | –

* Significantly different (P ≤ 0.05) from the chamber control group by Dunnett’s test.

^a^ Weights and weight changes are given as mean ± standard error. Subsequent calculations are based on animals surviving to the end of the study.

^b^ Number of animals surviving at day 17/number initially in group.

^c^ Days of death: 8, 8, 8, 8, 16.

^d^ Days of death: 1, 1, 1, 1, 2.

^e^ Day of deaths: 8.

^f^ Day of deaths: 1.

The absolute liver weights of 400 ppm males and 200 ppm females were significantly greater (21% and 19%, respectively) than those of the chamber controls (Table D-1). The relative liver weights of 400 ppm males and all surviving groups of exposed females were significantly greater (up to 19%) than those of the chamber controls. The absolute kidney weight of 200 ppm females was significantly greater (14%) than that of the chamber controls, and the relative kidney weights of all surviving groups of exposed males and 200 and 400 ppm females were significantly greater (up to 16%) than those of the chamber controls. In females, the absolute lung weights of the 100 and 200 ppm groups and the relative lung weight of the 100 ppm group were significantly greater (up to 25%) than those of the chamber controls.

There were no exposure-related microscopic findings.

Exposure concentration selection rationale: Based on the mortality of 800 and 1,600 ppm rats and a lack of significant histopathologic findings in rats exposed to α-pinene at 400 ppm or less, exposure concentrations of 0, 25, 50, 100, 200, and 400 ppm α-pinene were selected for the 3-month rat study.

### Three-month Study

All male rats survived to the end of the study (Table 3). Six 400 ppm female rats died during the study with no specific cause of death identified through gross examination or histopathologic analysis. The final mean body weights and mean body weight gains of females exposed to 400 ppm were significantly less than those of the chamber controls (Table 3; Figure 2); the final mean body weights and mean body weight gains of exposed males were similar to those of the chamber controls. No signs of toxicity (e.g., abnormal breathing or behavior) were noted during clinical observations.

Table 3 Survival and Body Weights of Rats in the Three-month Inhalation Study of α-Pinene^a^

Concentration (ppm) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 98 ± 3 | 335 ± 6 | 238 ± 5
25 | 10/10 | 98 ± 2 | 329 ± 11 | 231 ± 9 | 98
50 | 10/10 | 98 ± 2 | 333 ± 6 | 235 ± 5 | 99
100 | 10/10 | 98 ± 2 | 334 ± 7 | 236 ± 5 | 100
200 | 10/10 | 96 ± 2 | 330 ± 4 | 234 ± 4 | 98
400 | 10/10 | 97 ± 2 | 322 ± 6 | 225 ± 7 | 96
Female
0 | 10/10 | 89 ± 2 | 194 ± 3 | 105 ± 3
25 | 10/10 | 89 ± 2 | 199 ± 4 | 110 ± 4 | 102
50 | 10/10 | 89 ± 2 | 206 ± 4 | 117 ± 4 | 106
100 | 10/10 | 88 ± 2 | 199 ± 3 | 112 ± 2 | 103
200 | 10/10 | 88 ± 2 | 201 ± 3 | 113 ± 2 | 104
400 | 4/10^c^ | 89 ± 2 | 159 ± 5** | 72 ± 5** | 82

** Significantly different (P ≤ 0.01) from the chamber control group by Dunnett’s test.

^a^ Weights and weight changes are given as mean ± standard error. Subsequent calculations are based on animals surviving to the end of the study.

^b^ Number of animals surviving at 14 weeks/number initially in group.

^c^ Weeks of death: 6, 6, 6, 6, 8, 13.

Figure 2

Growth Curves for Rats Exposed to α-Pinene by Inhalation for Three Months

On day 4, there were mild exposure-related significant decreases in the leukocyte counts paired with mild significant decreases in the lymphocyte counts in 200 and 400 ppm male rats compared to concurrent controls (Table C-1). These decreases ameliorated by day 23. At week 14, there were mild significant decreases in erythrocyte counts, hemoglobin concentrations, and hematocrit values in males exposed to 100 ppm or greater. The leukocyte changes likely represent a secondary treatment-associated stress effect. The exact mechanisms for the mild decreases in the erythron are not known. Alanine aminotransferase activities were significantly decreased in males and females exposed to 50 ppm or greater at week 14. Significantly decreased alanine aminotransferase activities were also seen in 400 ppm male rats on days 4 and 23. Significant decreases in alkaline phosphatase activities were observed in 400 ppm males and 200 and 400 ppm females on day 4 and in males and females exposed to 100 ppm or greater at week 14. The reason for the decreases in these enzyme activities is not known but may be related to alterations in liver metabolism or enzyme inhibition. The remaining significant differences in hematology and clinical chemistry parameters were not considered to be toxicologically relevant.

In males, the absolute liver weight of the 400 ppm group and the relative liver weights of groups exposed to 100 ppm or greater were significantly greater (up to 17%) than those of the chamber controls (Table 4 and Table D-2). In females, the absolute liver weights of the 50, 100, and 200 ppm groups and the relative liver weights of all exposed groups were significantly greater (up to 17%) than those of the chamber controls. The absolute heart weights of 100 and 200 ppm females and the relative heart weights of females exposed to 100 ppm or greater were significantly greater (up to 11%) than those of the chamber controls. The absolute kidney weights of male rats exposed to 100 ppm or greater and the relative kidney weights of males exposed to 50 ppm or greater were significantly greater (absolute: 11% to 25%; relative: 4% to 31%) than those of the chamber controls. In females, the absolute kidney weights of the 50 and 200 ppm groups and the relative kidney weights of the 200 and 400 ppm groups were significantly greater (up to 18%) than those of the chamber controls. The absolute and relative thymus weights of 400 ppm females and the relative thymus weight of 200 ppm females were significantly less than those of the chamber controls. The absolute and relative spleen weights of 400 ppm males were significantly greater than those of the chamber control group. The weight changes in lymphoid tissues were not accompanied by clinical chemistry or histopathologic changes indicative of immunotoxicity and, therefore, were not considered toxicologically relevant. With the exception of the male kidney, the organ weight changes in male and female rats were not accompanied by histopathologic lesions.

Table 4 Selected Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the Three-month Inhalation Study of α-Pinene^a^

| Chamber Control | 25 ppm | 50 ppm | 100 ppm | 200 ppm | 400 ppm
Male
n | 10 | 10 | 10 | 10 | 10 | 10
Necropsy body wt | 335 ± 6 | 329 ± 11 | 333 ± 6 | 334 ± 7 | 330 ± 4 | 322 ± 6
R. Kidney
Absolute | 1.025 ± 0.019 | 1.012 ± 0.037 | 1.061 ± 0.026 | 1.137 ± 0.027** | 1.209 ± 0.020** | 1.286 ± 0.039**
Relative | 3.058 ± 0.038 | 3.073 ± 0.037 | 3.186 ± 0.042* | 3.405 ± 0.036** | 3.660 ± 0.040** | 3.991 ± 0.056**
Liver
Absolute | 10.54 ± 0.27 | 10.31 ± 0.40 | 10.44 ± 0.32 | 11.08 ± 0.36 | 11.37 ± 0.26 | 11.87 ± 0.45*
Relative | 31.402 ± 0.375 | 31.270 ± 0.317 | 31.298 ± 0.490 | 33.152 ± 0.569* | 34.393 ± 0.531** | 36.807 ± 0.864**
Spleen
Absolute | 0.628 ± 0.012 | 0.630 ± 0.013 | 0.663 ± 0.014 | 0.659 ± 0.009 | 0.655 ± 0.010 | 0.677 ± 0.023*
Relative | 1.874 ± 0.028 | 1.925 ± 0.045 | 1.997 ± 0.058 | 1.978 ± 0.030 | 1.983 ± 0.022 | 2.103 ± 0.057**
Female
n | 10 | 10 | 10 | 10 | 10 | 4
Necropsy body wt | 194 ± 3 | 199 ± 4 | 206 ± 4 | 199 ± 3 | 201 ± 3 | 159 ± 5**
Heart
Absolute | 0.584 ± 0.010 | 0.612 ± 0.012 | 0.618 ± 0.010 | 0.629 ± 0.012* | 0.638 ± 0.011** | 0.530 ± 0.006*
Relative | 3.010 ± 0.039 | 3.081 ± 0.054 | 3.002 ± 0.041 | 3.156 ± 0.034* | 3.175 ± 0.049* | 3.349 ± 0.084**
R. Kidney
Absolute | 0.618 ± 0.011 | 0.641 ± 0.009 | 0.680 ± 0.013** | 0.659 ± 0.015 | 0.679 ± 0.014** | 0.595 ± 0.021
Relative | 3.185 ± 0.040 | 3.230 ± 0.062 | 3.301 ± 0.041 | 3.307 ± 0.058 | 3.376 ± 0.050* | 3.757 ± 0.138**
Liver
Absolute | 5.486 ± 0.179 | 5.990 ± 0.121 | 6.270 ± 0.115** | 6.269 ± 0.151** | 6.424 ± 0.144** | 4.840 ± 0.247
Relative | 28.216 ± 0.637 | 30.152 ± 0.550** | 30.438 ± 0.319** | 31.459 ± 0.586** | 31.916 ± 0.317** | 30.470 ± 0.715**
Thymus
Absolute | 0.347 ± 0.012 | 0.349 ± 0.010 | 0.352 ± 0.010 | 0.346 ± 0.010 | 0.330 ± 0.014 | 0.204 ± 0.010**
Relative | 1.785 ± 0.054 | 1.751 ± 0.029 | 1.707 ± 0.041 | 1.739 ± 0.048 | 1.638 ± 0.058* | 1.286 ± 0.035**

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

There were significantly decreased numbers of cauda sperm in 200 and 400 ppm males with 19% lower sperm per cauda in the 200 and 400 ppm groups compared to the chamber controls (Table 5 and Table E-1). Females in the 400 ppm group displayed an apparent increase in cycle length and a slight increase in the percentage of the cycle spent in metestrus, relative to the chamber control group (Table E-2). However, the apparent increase in cycle length may be secondary to stress, as evidenced by lower body weight and mortality in the 400 ppm group. Alternatively, the apparent changes in the 400 ppm females may have been an artifact of having too few animals available to allow for meaningful interpretation. In addition, consideration of the complete cycle using a Markov analysis indicated that these exposed females did not spend significantly more time in any of the estrous stages than did the chamber control group (Table E-3). The minor changes in cycle length observed only in the exposure concentration group exhibiting overt toxicity, combined with a lack of ovarian histopathology findings, did not provide sufficient evidence for female reproductive toxicity potential under the conditions of the study. Based on these results, α-pinene exposure by inhalation exhibits the potential to be a reproductive toxicant in male rats, but not in female rats.

Table 5 Epididymal Spermatozoal Measurements for Male Rats in the Three-month Inhalation Study of α-Pinene^a^

| Chamber Control | 100 ppm | 200 ppm | 400 ppm
n | 10 | 10 | 9 | 10
Epididymal spermatozoal measurements
Sperm motility (%) | 91.73 ± 1.26 | 91.40 ± 0.93 | 91.24 ± 0.80 | 90.93 ± 0.89
Sperm (10^3^/mg cauda epididymis) | 615.0 ± 34.3 | 596.5 ± 31.8 | 526.3 ± 19.0 | 547.4 ± 14.0
Sperm (10^6^/cauda epididymis) | 120.89 ± 6.79 | 113.16 ± 3.11 | 97.52 ± 3.51** | 98.40 ± 3.02**

** Significantly different (P ≤ 0.01) from the chamber control group by Shirley’s test.

^a^ Data are presented as mean ± standard error.

Renal tubule lesions including granular casts, hyaline droplets, and nephropathy were observed in male rats exposed to α-pinene (Table 6 and Table A-1). In all male groups exposed to α-pinene, there were significantly increased incidences of granular casts and hyaline droplet accumulation and the severities of these lesions increased with increasing exposure concentration. Granular casts were not observed in the chamber controls (Figure 4 and Figure 5), and in exposed groups the mean severity ranged from minimal in males exposed to 25 ppm to moderate in males exposed to 400 ppm. Casts occurred in the lumens of the tubules along the outer medulla and were composed of pale, eosinophilic, granular cell debris that filled and dilated the tubular lumens (Figure 6 and Figure 7).

Table 6 Incidences of Nonneoplastic Lesions of the Kidney in Male Rats in the Three-month Inhalation Study of α-Pinene

| Chamber Control | 25 ppm | 50 ppm | 100 ppm | 200 ppm | 400 ppm
Number Examined Microscopically | 10 | 10 | 10 | 10 | 10 | 10
Casts, Granular^a^ | 0 | 9** (1.0)^b^ | 10** (1.2) | 10** (1.5) | 10** (2.5) | 10** (3.0)
Accumulation, Hyaline Droplet | 1 (2.0) | 10** (1.1) | 10** (1.8) | 10** (2.0) | 10** (2.7) | 10** (3.0)
Nephropathy | 9 (1.1) | 10 (1.6) | 10 (2.0) | 10 (2.0) | 10 (2.5) | 10 (3.0)

** Significantly different (P ≤ 0.01) from the chamber control group by the Fisher exact test.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Figure 4

Kidney of a Chamber Control Male F344/N Rat in the Three-month Inhalation Study of α-Pinene (H&E)

Figure 5

Higher Magnification of Figure 4 (H&E)

Figure 6

Kidney of a Male F344/N Rat Exposed to 400 ppm α-Pinene by Inhalation for Three Months (H&E)

Note the numerous tubules (arrows) containing granular casts, which are considered a hallmark of α2µ globulin nephropathy in male rats.

Figure 7

Higher Magnification of Figure 6 (H&E)

Hyaline droplet accumulation occurred in the cytoplasm of the renal proximal convoluted tubule epithelial cells, and the severity ranged from minimal in males exposed to 25 ppm to moderate in males exposed to 400 ppm (Table 6 and Table A-1). In the chamber controls, the droplets occurred as individual, uniformly fine, round eosinophilic globules in the epithelial cells of clusters of tubules (Figure 8 and Figure 9). Intervening areas of tubules devoid of cytoplasmic droplets separated these clusters of tubules. As the exposure concentration and severity increased, the droplets were increasingly larger and varied from round to rectangular and often occurred in clumps (Figure 10 and Figure 11). At the highest severity grade, the accumulations varied from small to large irregular globular to rectangular to crystalline, refractile forms. Although evident in the H&E-stained sections, when stained with the Mallory-Heidenhain method for visualization of protein, accumulations were more prominent and allowed better quantification and characterization of the droplets.

Figure 8

Kidney of a Chamber Control Male F344/N Rat in the Three-month Inhalation Study of α-Pinene (H&E)

Figure 9

Kidney of a Chamber Control Male F344/N Rat in the Three-month Inhalation Study of α-Pinene (Mallory-Heidenhain)

Note the presence of small protein droplets (arrows) that are normally present in the renal tubule epithelium of male rats; the inset highlights the protein droplets.

Figure 10

α2µ Globulin Nephropathy in the Kidney of a Male F344/N Rat Exposed to 400 ppm α-Pinene by Inhalation for Three Months (H&E)

Note the accumulation of large, irregular, coalescing protein droplets (arrows) in the renal tubule epithelium.

Figure 11

α2µ Globulin Nephropathy in the Kidney of a Male F344/N Rat Exposed to 400 ppm α-Pinene by Inhalation for Three Months (Mallory-Heidenhain)

Note the accumulation of large, irregular, coalescing protein droplets (arrows) in the renal tubule epithelium; the inset highlights the large irregular, coalescing protein droplets.

With the exception of one chamber control rat, nephropathy occurred in all males, with the mean severity increasing from minimal in chamber control males to moderate in males exposed to 400 ppm (Table 6 and Table A-1). Nephropathy was characterized by multifocal clusters of regenerating tubules surrounded by thickening of tubular basement membranes, individual tubular epithelial cell necrosis, widely scattered protein casts, and associated infiltrates of lymphocytes within the interstitium.

There were no exposure-related microscopic findings in females, including those that died before the end of the study.

## Mice

### Two-week Study

All 800 and 1,600 ppm males and females died early (Table 7). The final mean body weights and mean body weight gains of all surviving groups of exposed mice were similar to those of the chamber controls. Lethargy and abnormal breathing were observed in three 800 ppm males and two 1,600 ppm males, and lethargy was observed in one 1,600 ppm female. Ataxia was observed in two 800 ppm males, two 1,600 ppm males, and four 800 ppm females.

Table 7 Survival and Body Weights of Mice in the Two-week Inhalation Study of α-Pinene^a^

Concentration (ppm) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 5/5 | 23.7 ± 0.4 | 27.9 ± 0.7 | 4.1 ± 0.4
100 | 5/5 | 23.4 ± 0.7 | 26.7 ± 0.7 | 3.4 ± 0.3 | 96
200 | 5/5 | 23.1 ± 0.8 | 26.6 ± 0.9 | 3.5 ± 0.4 | 95
400 | 5/5 | 23.9 ± 0.5 | 27.0 ± 0.6 | 3.1 ± 0.2 | 97
800 | 0/5^c^ | 23.5 ± 0.5 | – | – | –
1,600 | 0/5^d^ | 23.5 ± 0.6 | – | – | –
Female
0 | 5/5 | 20.2 ± 0.4 | 23.0 ± 0.4 | 2.8 ± 0.3
100 | 5/5 | 20.6 ± 0.5 | 23.6 ± 0.5 | 3.0 ± 0.3 | 103
200 | 5/5 | 20.2 ± 0.5 | 23.2 ± 0.7 | 3.0 ± 0.7 | 101
400 | 5/5 | 19.9 ± 0.5 | 22.6 ± 0.5 | 2.7 ± 0.3 | 99
800 | 0/5^e^ | 19.8 ± 0.3 | – | – | –
1,600 | 0/5^f^ | 19.8 ± 0.2 | – | – | –

^a^ Weights and weight changes are given as mean ± standard error. Subsequent calculations are based on animals surviving to the end of the study.

^b^ Number of animals surviving at day 18/number initially in group.

^c^ Days of death: 2, 2, 3, 4, 16.

^d^ Days of death: 1, 1, 1, 1, 2.

^e^ Day of deaths: 2.

^f^ Day of deaths: 1.

The absolute and relative liver weights of 400 ppm males and females and the relative liver weight of 200 ppm males were significantly greater (up to 20%) than those of the chamber controls (Table D-3). The absolute and relative kidney weights of 100 ppm females were significantly greater (18% and 15%, respectively) than those of the chamber controls as was the relative kidney weight of 400 ppm males (12%).

In the nose, there were significantly increased incidences of minimal olfactory epithelial degeneration in 800 and 1,600 ppm males (chamber controls, 0/5; 100 ppm, 0/0; 200 ppm, 0/0; 400 ppm, 0/5; 800 ppm, 5/5; 1,600 ppm, 4/5) and females (0/5, 0/0, 0/0, 0/5, 4/5, 5/5). Degeneration was characterized by slight disorganization of the normal olfactory architecture in the Level I and II nasal sections and the epithelial cells in the mid layers of the olfactory epithelium were often pyknotic. The mucosa often had an undulating appearance, and strands of proteinaceous debris and/or mucus were present in the nasal passages.

Exposure concentration selection rationale: Based on decreased survival and nonneoplastic lesions in the nose of 800 and 1,600 ppm males and females observed in this study, exposure concentrations of 0, 25, 50, 100, 200, and 400 ppm α-pinene were selected for the 3-month study in mice.

### Three-month Study

All mice survived to the end of the study (Table 8). The final mean body weights and body weight gains of exposed males and females were similar to those of the chamber controls (Table 8; Figure 3). No clinical findings related to α-pinene exposure were observed.

Table 8 Survival and Body Weights of Mice in the Three-month Inhalation Study of α-Pinene^a^

Concentration (ppm) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 22.9 ± 0.2 | 37.1 ± 0.6 | 14.3 ± 0.6
25 | 10/10 | 23.0 ± 0.3 | 36.9 ± 0.7 | 13.9 ± 0.8 | 99
50 | 10/10 | 22.7 ± 0.3 | 38.3 ± 0.9 | 15.6 ± 0.8 | 103
100 | 10/10 | 22.5 ± 0.2 | 35.9 ± 0.7 | 13.4 ± 0.7 | 97
200 | 10/10 | 22.8 ± 0.3 | 35.5 ± 1.0 | 12.7 ± 0.9 | 96
400 | 10/10 | 22.8 ± 0.2 | 36.2 ± 0.5 | 13.5 ± 0.4 | 98
Female
0 | 10/10 | 19.5 ± 0.4 | 31.5 ± 0.6 | 12.0 ± 0.5
25 | 10/10 | 19.6 ± 0.4 | 30.3 ± 0.6 | 10.8 ± 0.7 | 96
50 | 10/10 | 19.7 ± 0.3 | 32.7 ± 0.7 | 12.9 ± 0.7 | 104
100 | 10/10 | 19.7 ± 0.4 | 31.5 ± 1.1 | 11.8 ± 0.9 | 100
200 | 10/10 | 19.3 ± 0.3 | 30.7 ± 0.6 | 11.4 ± 0.6 | 97
400 | 10/10 | 19.4 ± 0.3 | 30.6 ± 0.5 | 11.2 ± 0.4 | 97

^a^ Weights and weight changes are given as mean ± standard error.

^b^ Number of animals surviving at 14 weeks/number initially in group.

Figure 3

Growth Curves for Mice Exposed to α-Pinene by Inhalation for Three Months

At the end of the study, there were small but statistically significant decreases in erythrocyte counts in 200 and 400 ppm females and in the hemoglobin concentration and the hematocrit value in 400 ppm females compared to concurrent controls (Table C-2). Decreases in erythrocyte count and hematocrit value also occurred in 400 ppm males. Leukocyte and lymphocyte counts were significantly decreased in 400 ppm males. The leukocyte changes likely represent a secondary treatment-associated stress effect. The exact mechanism for the mild decreases in the erythron are not known. Other significant changes in hematology parameters were not toxicologically relevant.

The absolute liver weights of 400 ppm males and females and the relative liver weights of 200 and 400 ppm males and 100, 200, and 400 ppm females were significantly greater (up to 24%) than those of the chamber controls (Table 9 and Table D-4). The absolute and relative thymus weights of 400 ppm males were significantly less than those of the chamber controls. The absolute kidney weights of 200 and 400 ppm males were significantly less than those of the chamber controls (11% and 7%, respectively). These organ weight changes were not accompanied by histopathologic lesions.

Table 9 Selected Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Three-month Inhalation Study of α-Pinene^a^

| Chamber Control | 25 ppm | 50 ppm | 100 ppm | 200 ppm | 400 ppm
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 37.1 ± 0.6 | 36.9 ± 0.7 | 38.3 ± 0.9 | 35.9 ± 0.7 | 35.5 ± 1.0 | 36.2 ± 0.5
R. Kidney
Absolute | 0.330 ± 0.006 | 0.318 ± 0.009 | 0.336 ± 0.010 | 0.309 ± 0.008 | 0.295 ± 0.006* | 0.307 ± 0.007*
Relative | 8.903 ± 0.167 | 8.629 ± 0.208 | 8.793 ± 0.267 | 8.617 ± 0.205 | 8.348 ± 0.145 | 8.469 ± 0.155
Liver
Absolute | 1.617 ± 0.022 | 1.589 ± 0.028 | 1.702 ± 0.040 | 1.637 ± 0.024 | 1.660 ± 0.043 | 1.957 ± 0.057**
Relative | 43.671 ± 0.880 | 43.123 ± 0.458 | 44.487 ± 0.806 | 45.651 ± 0.678 | 46.903 ± 0.750* | 54.009 ± 1.465**
Thymus
Absolute | 0.066 ± 0.004 | 0.063 ± 0.004 | 0.067 ± 0.003 | 0.057 ± 0.001 | 0.062 ± 0.004 | 0.051 ± 0.003**
Relative | 1.777 ± 0.081 | 1.699 ± 0.090 | 1.742 ± 0.063 | 1.591 ± 0.052 | 1.739 ± 0.115 | 1.397 ± 0.081**
Female
Necropsy body wt | 31.5 ± 0.6 | 30.3 ± 0.6 | 32.7 ± 0.7 | 31.5 ± 1.1 | 30.7 ± 0.6 | 30.6 ± 0.5
Liver
Absolute | 1.466 ± 0.041 | 1.475 ± 0.053 | 1.442 ± 0.036 | 1.548 ± 0.053 | 1.587 ± 0.037 | 1.730 ± 0.032**
Relative | 46.542 ± 0.988 | 48.567 ± 1.239 | 44.214 ± 0.880 | 49.280 ± 0.672* | 51.728 ± 0.795** | 56.511 ± 0.705**

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ test.

** Significantly different (P ≤ 0.01) from the chamber control group by Williams’ or Dunnett’s test.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

There were significantly decreased numbers of sperm per mg cauda in 200 and 400 ppm males (24% and 37%, respectively) and cauda sperm in 100, 200, and 400 ppm males (25%, 33%, and 40%, respectively; Table 10 and Table E-4). There were no changes in the proportion of regularly cycling females, estrous cycle length, or percentage of time spent in the individual stages of the estrous cycle of female mice at any exposure concentration (Table E-5) and there were no ovarian histopathologic findings. Therefore, α-pinene exposure via inhalation exhibits the potential to be a reproductive toxicant in male mice, but not in female mice.

Table 10 Epididymal Spermatozoal Measurements of Male Mice in the Three-month Inhalation Study of α-Pinene^a^

| Chamber Control | 100 ppm | 200 ppm | 400 ppm
n | 10 | 10 | 10 | 10
Epididymal spermatozoal measurements
Sperm motility (%) | 90.25 ± 0.34 | 88.31 ± 0.86 | 89.74 ± 0.80 | 87.95 ± 1.08
Sperm (10^3^/mg cauda epididymis) | 704.8 ± 64.9 | 690.7 ± 55.9 | 537.5 ± 27.0* | 445.8 ± 13.5**
Sperm (10^6^/cauda epididymis) | 24.45 ± 0.95 | 18.40 ± 0.41** | 16.48 ± 0.72** | 14.64 ± 0.25**

* Significantly different (P ≤ 0.05) from the chamber control group by Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error.

In the urinary bladder, there were significantly increased incidences of transitional epithelium hyperplasia in males and females exposed to 100 ppm or greater (Table 11, Table A-3, and Table A-4). The incidences and the severities of this lesion increased in an exposure concentration-related manner. This lesion was characterized by a relatively uniform increase in mucosal thickness with an increase in the size of the transitional epithelial cells, and the number of epithelial cell layers from two or three in controls (Figure 12 and Figure 13) to four or more layers in affected mice (Figure 14 and Figure 15). The hyperplastic epithelium had cells of more uniform size, with loss of the superficial large cells and a less distinct basal cell layer. Cells frequently exhibited increased amounts of dark eosinophilic to slightly basophilic cytoplasm with enlarged nuclei and occasional mitotic figures. Individually necrotic transitional epithelial cells were sometimes scattered along the luminal surface.

Table 11 Incidences of Nonneoplastic Lesions of the Urinary Bladder in Mice in the Three-month Inhalation Study of α-Pinene

| Chamber Control | 25 ppm | 50 ppm | 100 ppm | 200 ppm | 400 ppm
Male
Number Examined Microscopically | 10 | 10 | 10 | 10 | 10 | 10
Transitional Epithelium, Hyperplasia^a^ | 0 | 0 | 0 | 7** (1.0)^b^ | 10** (2.0) | 10** (2.5)
Female
Number Examined Microscopically | 10 | 10 | 10 | 10 | 10 | 10
Transitional Epithelium, Hyperplasia | 0 | 0 | 0 | 6** (1.0) | 10** (1.6) | 10** (2.2)

** Significantly different (P ≤ 0.01) from the chamber control group by the Fisher exact test.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Figure 12

Urinary Bladder of a Chamber Control Female B6C3F1/N Mouse in the Three-month Inhalation Study of α-Pinene (H&E)

Note the normal transitional epithelium (arrows).

Figure 13

Higher Magnification of Figure 12 Showing Normal Transitional Epithelium (Arrow) (H&E)

Figure 14

Urinary Bladder of a Female B6C3F1/N Mouse Exposed to 400 ppm α-Pinene by Inhalation for Three Months (H&E)

Note the markedly hyperplastic transitional epithelium (arrows).

Figure 15

Higher Magnification of Figure 14 Showing the Hyperplastic Transitional Epithelium (Arrow) (H&E)

## Genetic Toxicology

α-Pinene (5 to 10,000 µg/plate) was not mutagenic in Salmonella typhimurium strains TA98 or TA100 or in Escherichia coli strain WP2 uvrA/pKM101 with or without rat liver S9 activation enzymes (Table B-1).

No increases in the frequencies of micronucleated erythrocytes (biomarkers of chromosomal damage) were observed in peripheral blood of male or female mice in the 3-month inhalation study (Table B-2). In addition, no significant changes in the percentages of polychromatic erythrocytes (immature erythrocytes) were noted in either male or female mice exposed to α-pinene, indicating an absence of bone marrow toxicity.