# Materials and Methods

## Procurement and Characterization of α-Pinene

α-Pinene was obtained from Millennium Specialty Chemicals (Jacksonville, FL) in one lot (4KB705) that was used in the 2-week and 3-month studies. Identity and purity analyses were conducted by the study laboratory at Battelle Toxicology Northwest (Richland, WA), Chemir Analytical Services (Maryland Heights, MO), Galbraith Laboratories, Inc. (Knoxville, TN), and Huffman Laboratories, Inc. (Golden, CO) (Appendix F). Reports on analyses performed in support of the α-pinene studies are on file at the National Institute of Environmental Health Sciences.

The chemical, a colorless oily liquid with a strong piney odor, was identified as α-pinene by Chemir Analytical Services using infrared and ^1^H-nuclear magnetic resonance spectroscopy. All spectra were consistent with the literature reference spectra.

Karl Fischer titration indicated a water content of 27 ppm. Elemental analyses for carbon, hydrogen, nitrogen, and sulfur were in agreement with the theoretical values for α-pinene. Gas chromatography with flame ionization detection (GC/FID) indicated one major peak accounting for approximately 96% of the total integrated peak area and three impurity peaks with areas exceeding 0.1% of the total peak area; two of these peaks matched the retention times for prepared standards of camphene (1.77%) and β-pinene (1.73%). Gas chromatography with mass spectrometry (GC/MS) identified the third impurity as tricyclene (0.51%). Enantiomeric composition analysis using GC/FID with a chiral separation column indicated that the lot was 69% (+)-α-pinene and 31% (−)-α-pinene. The overall purity of the lot was determined to be approximately 96%. Analysis using GC/MS indicated that approximately 15 to 16 ppm butylated hydroxy toluene, a free radical scavenger, was present in the lot to prevent oxidation of α-pinene.

To ensure stability, the bulk chemical was stored at 17°C in the original shipping containers (55-gallon metal drums). Periodic reanalyses of the bulk chemical were performed during the 2-week and 3-month studies by the study laboratory using GC/MS, and no degradation of the bulk chemical was detected.

## Vapor Generation and Exposure System

The vapor transport lines and all dilution air were heated, and α-pinene was pumped through a preheater (for the 2-week studies) and into a heated glass column filled with glass beads that increased the surface area for vaporization. Heated nitrogen entered the column from below and assisted in vaporizing the chemical while conveying it into a short distribution manifold. Concentration in the manifold was determined by the chemical pump rate, nitrogen flow rate, and dilution air flow rate. The pressure in the distribution manifold was kept fixed to ensure constant flow through the manifold and into all chambers as the flow of vapor to each chamber was adjusted.

Metering valves at the manifold controlled flow to each chamber through individual Teflon^®^ delivery lines that carried the vapor from the manifold to three-way exposure valves at the chamber inlets. The exposure valves diverted vapor delivery to exposure chamber exhaust until the generation system was stable and exposures were ready to proceed. To initiate exposure, the chamber exposure valves were rotated to allow the α-pinene vapor to flow to each exposure chamber inlet duct where it was further diluted with filtered, conditioned air to achieve the desired exposure concentration.

The study laboratory designed the inhalation exposure chamber (Lab Products, Inc., Seaford, DE) so that uniform vapor concentrations could be maintained throughout the chamber with the catch pans in place. The total active mixing volume of each chamber was 1.7 m^3^. A condensation particle detector was used with and without animals in the exposure chambers. No particle counts above the minimum resolvable level (approximately 200 particles/cm^3^) were detected.

## Vapor Concentration Monitoring

Summaries of the chamber vapor concentrations are given in Table F-2 and Table F-3. Chamber and room concentrations of α-pinene were monitored by an on-line gas chromatograph. Samples were drawn from each exposure chamber approximately every 20 minutes during each 6-hour exposure period. A 16-port stream select valve directed a continuous stream of sampled atmosphere to a six-port sampling valve with a sample loop, housed in a dedicated valve oven. A vacuum regulator maintained a constant vacuum in the sample loop to compensate for variations in sample line pressure. An in-line flow meter between the vacuum regulator and the gas chromatograph allowed digital measurement of sample flow. The on-line gas chromatograph was checked throughout the day for instrument drift against an on-line standard vapor of α-pinene in nitrogen supplied by a standard generator. The on-line gas chromatograph was recalibrated as required to meet acceptance criteria. Calibration was performed by a comparison of chamber concentration data to data from grab samples that were collected with activated coconut charcoal gas sampling tubes, extracted with toluene containing butylbenzene as an internal standard, and analyzed using an off-line gas chromatograph. Known volumes of chamber atmosphere were sampled at a constant flow rate ensured by a calibrated critical orifice. The off-line gas chromatograph was calibrated with gravimetrically prepared standards of α-pinene containing butylbenzene as an internal standard in toluene.

## Chamber Atmosphere Characterization

Buildup and decay rates for chamber vapor concentrations were determined with and without animals present in the chambers. At a chamber airflow rate of 15 air changes per hour, the theoretical value for the time to achieve 90% of the target concentration after the beginning of vapor generation (T_90_) and the time for the chamber concentration to decay to 10% of the target concentration after vapor generation was terminated (T_10_) was approximately 9.4 minutes. T_90_ values of 12 and 10 minutes were selected for the 2-week and 3-month studies, respectively.

Evaluations of chamber uniformity and persistence and monitoring for α-pinene degradation impurities were conducted periodically throughout the studies by gas chromatography. Chamber uniformity was maintained; no degradation was detected.

## Animal Source

Male and female F344/N rats and B6C3F1/N mice were obtained from the NTP colony maintained at Taconic Farms, Inc. (Germantown, NY), for the 2-week and 3-month studies.

## Two-week Studies

On receipt, the rats and mice were 4 weeks old. Animals were quarantined for 11 days and were 6 weeks old on the first day of the studies. Before the studies began, five extra male and five female rats and mice were randomly selected for parasite evaluation and gross observation for evidence of disease. At the end of the studies, serologic analyses were performed on five male and five female chamber control rats and mice using the protocols of the NTP Sentinel Animal Program (Appendix H). Groups of five male and five female rats and mice were exposed to α-pinene via whole body inhalation at concentrations of 0, 100, 200, 400, 800, or 1,600 ppm, 6 hours plus T_90_ (12 minutes) per day, 5 days per week for 16 (rats) or 17 (mice) days. Concentrations were selected based on studies of turpentine toxicity performed by Chapman^41^ that involved exposure of rats to roughly estimated (by the NTP) concentrations of 5,000 to 10,000 mg/m^3^ (897 to 1,795 ppm) turpentine via inhalation for 6.5 to 293 total hours over periods ranging from 5 days to 14 months with no chemical-related lesions observed in the kidneys. Feed was available ad libitum except during exposure periods; water was available ad libitum. Rats and mice were housed individually. Clinical findings were recorded twice daily on exposure days for rats and mice. The animals were weighed initially, on days 6 and 13, and at the end of the studies. Details of the study design and animal maintenance are summarized in Table 1.

Table 1 Experimental Design and Materials and Methods in the Inhalation Studies of α-Pinene

Two-week Studies | Three-month Studies
Study Laboratory
Battelle Toxicology Northwest (Richland, WA) | Battelle Toxicology Northwest (Richland, WA)
Strain and Species
F344/N rats | F344/N rats
B6C3F1/N mice | B6C3F1/N mice
Animal Source
Taconic Farms, Inc. (Germantown, NY) | Taconic Farms, Inc. (Germantown, NY)
Time Held Before Studies
11 days | Rats: 12 (males) or 13 (females) days
| Mice: 12 days
Average Age When Studies Began
6 weeks | Rats: 6 weeks
| Mice: 5 to 6 weeks
Date of First Exposure
November 29, 2004 | Rats: March 28 (males) or 29 (females), 2005
| Mice: March 28, 2005
Duration of Exposure
6 hours plus T_90_ (12 minutes) per day, 5 days per week, for 16 (rats) or 17 (mice) days | 6 hours plus T_90_ (10 minutes) per day, 5 days per week, for 14 weeks
Date of Last Exposure
Rats: December 14, 2004 | Rats: June 27 (males) or 28 (females), 2005
Mice: December 15, 2004 | Mice: June 29 (males) or 30 (females), 2005
Necropsy Dates
Rats: December 15, 2004 | Rats: June 28 (males) or 29 (females), 2005
Mice: December 16, 2004 | Mice: June 30 (males) or July 1 (females), 2005
Average Age at Necropsy
8 weeks | 19 weeks
Size of Study Groups
5 males and 5 females | 10 males and 10 females
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights. | Same as 2-week studies
Animals per Cage
1 | 1
Method of Animal Identification
Tail tattoo | Same as 2-week studies
Diet
NTP-2000 irradiated wafers (Zeigler Brothers, Inc., Gardners, PA), available ad libitum (except during exposure periods); changed weekly | Same as 2-week studies
Water
Tap water (Richland, WA, municipal supply) via automatic watering system (Edstrom Industries, Waterford, WI); available ad libitum | Same as 2-week studies
Cages
Stainless steel, wire bottom (Lab Products, Inc., Seaford, DE); changed weekly | Same as 2-week studies; rotated weekly
Cageboard
Untreated paper cage pan liner (Shepherd Specialty Papers, Kalamazoo, MI), changed daily | Same as 2-week studies
Chamber Air Supply Filters
Single HEPA, changed annually; charcoal (RSE, Inc., New Baltimore, MI), new at study start; Purafil (Environmental Systems, Lynnwood, WA), new at study start | Same as 2-week studies
Chambers
Stainless steel, excreta pan at each of six levels (Lab Products, Inc., Seaford, DE); chambers changed weekly; excreta pans changed daily | Same as 2-week studies
Chamber Environment
Temperature: 72° ± 3°F | Temperature: 72° ± 3°F
Relative humidity: 50% ± 15% | Relative humidity: 50% ± 15%
Room fluorescent light: 12 hours/day | Room fluorescent light: 12 hours/day
Chamber air changes: 15 ± 2/hour | Chamber air changes: 15 ± 2/hour
Exposure Concentrations
0, 100, 200, 400, 800, and 1,600 ppm | 0, 25, 50, 100, 200, and 400 ppm
Type and Frequency of Observation
Observed twice daily; animals were weighed initially, on days 6 and 13, and at the end of the studies; clinical findings were recorded twice daily on exposure days and at the end of the studies. | Observed twice daily; core study animals were weighed initially, on day 7 (female rats), day 8 (male rats and male and female mice), weekly thereafter, and at the end of the studies; clinical findings were recorded on day 7 (female rats), day 8 (male rats and male and female mice), weekly thereafter, and at the end of the studies.
Method of Kill
Carbon dioxide asphyxiation | Same as 2-week studies
Necropsy
Necropsies were performed on all animals. Organs weighed were heart, right kidney, liver, lung, right testis, and thymus. | Necropsies were performed on all core study animals. Organs weighed were heart, right kidney, liver, lung, spleen, right testis, and thymus.
Clinical Pathology
None | Blood was collected from the retroorbital plexus of clinical pathology rats on days 4 and 23 and from core study animals at the end of the studies for hematology and clinical chemistry (rats only). Hematology: hematocrit; packed cell volume; hemoglobin; erythrocyte, reticulocyte, and platelet counts; Howell-Jolly bodies (mice); mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; and leukocyte counts and differentials. Clinical chemistry: urea nitrogen, creatinine, total protein, albumin, globulin, alanine aminotransferase, alkaline phosphatase, creatine kinase, sorbitol dehydrogenase, and bile salts
Histopathology
Histopathology was performed on 0, 400, 800, and 1,600 ppm rats and mice. In addition to gross lesions and tissue masses, the lung and nose were examined. | Complete histopathology was performed on 0 and 400 ppm core study rats and mice and 200 ppm female rats. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone, brain, clitoral gland, esophagus, eyes, gallbladder (mice), Harderian gland, heart and aorta, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, larynx, liver, lung and mainstem bronchi, lymph nodes (mandibular, mesenteric, bronchial, mediastinal), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, skin, spleen, stomach (forestomach and glandular), testis with epididymis and seminal vesicles, thymus, thyroid gland, trachea, urinary bladder, and uterus. The liver of male rats, kidney of rats and mice, and urinary bladder of mice were examined in the remaining groups.
Sperm Motility and Vaginal Cytology
None | At the end of the studies, sperm samples were collected from male animals in the 0, 100, 200, and 400 ppm groups for sperm motility evaluations. The following parameters were evaluated: sperm heads per testis and per gram testis, spermatid counts, and epididymal spermatozoal motility and concentration. The left cauda, left epididymis, and left testis were weighed. Vaginal samples were collected for up to 12 consecutive days prior to the end of the studies from females exposed to 0, 100, 200, or 400 ppm for vaginal cytology evaluations. The percentage of time spent in the various estrous cycle stages and estrous cycle length were evaluated.

Necropsies were performed on all rats and mice. The heart, right kidney, liver, lung, right testis, and thymus were weighed. Histopathologic examinations were performed on all chamber control, 400, 800 and 1,600 ppm rats and mice. Table 1 lists the tissues and organs examined.

## Three-month Studies

On receipt, the rats and mice were approximately 4 weeks old. Animals were quarantined for 12 (male rats and male and female mice) or 13 (female rats) days and were 5 to 6 weeks old on the first day of the studies. Before the studies began, five male and five female rats and mice were randomly selected for parasite evaluation and gross observation for evidence of disease. Serologic analyses were performed on five male and five female sentinel rats and mice at 1 week and at the end of the studies using the protocols of the NTP Sentinel Animal Program (Appendix H).

Groups of 10 male and 10 female rats and mice were exposed to α-pinene via whole body inhalation at concentrations of 0, 25, 50, 100, 200, or 400 ppm, 6 hours plus T_90_ (10 minutes) per day, 5 days per week for 14 weeks. Groups of 10 male and 10 female clinical pathology rats were exposed to the same concentrations for 23 days. Feed was available ad libitum except during exposure periods; water was available ad libitum. Rats and mice were housed individually throughout the study period. Animal care and use are in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by the Association for the Assessment and Accreditation of Laboratory Animal Care International. Studies were approved by the Battelle Toxicology Northwest Animal Care and Use Committee and conducted in accordance with all relevant NIH and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines. Core study animals were weighed initially, and body weights and clinical findings were recorded on day 7 (female rats), day 8 (male rats and male and female mice), weekly thereafter, and at the end of the studies. Details of the study design and animal maintenance are summarized in Table 1. Information on feed composition and contaminants is provided in Appendix G.

Animals were anesthetized with carbon dioxide, and blood was collected from the retroorbital plexus of clinical pathology rats on days 4 and 23 and from core study rats and mice at the end of the studies for hematology and clinical chemistry (rats only) analyses. Blood samples for hematology analyses were placed in tubes containing potassium EDTA. Packed cell volume; hemoglobin concentration; erythrocyte, platelet, and leukocyte counts; mean cell volume; mean cell hemoglobin; and mean cell hemoglobin concentration were determined using an Abbott Cell-Dyn 3700 Analyzer (Abbott Diagnostics Systems, Abbott Park, IL). Manual hematocrit values were determined using a microcentrifuge (Heraeus Haemofuge; Hanau, Germany) and a Damon/IEC capillary reader (International Equipment Co., Needham Heights, MA) for comparison to Cell-Dyn values for packed cell volume. Blood smears were stained with Romanowsky-type aqueous stain in a Wescor 1700 aerospray slide stainer (Wescor, Inc., Logan, UT). Leukocyte differential counts were based on classifying a minimum of 100 white cells. Reticulocytes were stained with new methylene blue and enumerated as a reticulocyte:erythrocyte ratio using the Miller disc method.^42^ Blood samples for clinical chemistry analyses were placed in tubes without anticoagulant and containing a separator gel, allowed to clot, and centrifuged. Parameters were determined using a Roche Hitachi 912 System (Roche Diagnostic Corporation, Indianapolis, IN). Table 1 lists the parameters measured.

At the end of the 3-month studies, samples were collected for sperm motility and vaginal cytology evaluations on rats and mice exposed to 0, 100, 200, or 400 ppm. The parameters evaluated are listed in Table 1. For 12 consecutive days prior to scheduled terminal sacrifice, the vaginal vaults of the females were moistened with saline, if necessary, and samples of vaginal fluid and cells were stained. Relative numbers of leukocytes, nucleated epithelial cells, and large squamous epithelial cells were determined and used to ascertain estrous cycle stage (i.e., diestrus, proestrus, estrus, and metestrus). Male animals were evaluated for sperm count and motility. The left testis and left epididymis were isolated and weighed. The tail of the epididymis (cauda epididymis) was then removed from the epididymal body (corpus epididymis) and weighed. Test yolk (rats) or modified Tyrode’s buffer (mice) was applied to slides and a small incision was made at the distal border of the cauda epididymis. The sperm effluxing from the incision were dispersed in the buffer on the slides, and the numbers of motile and nonmotile spermatozoa were counted for five fields per slide by two observers. Following completion of sperm motility estimates, each left cauda epididymis was placed in buffered saline solution. Caudae were finely minced, and the tissue was incubated in the saline solution and then heat fixed at 65°C. Sperm density was then determined microscopically with the aid of a hemacytometer. To quantify spermatogenesis, the testicular spermatid head count was determined by removing the tunica albuginea and homogenizing the left testis in phosphate-buffered saline containing 10% dimethyl sulfoxide. Homogenization-resistant spermatid nuclei were counted with a hemacytometer.

Necropsies were performed on all core study animals. The heart, right kidney, liver, lung, spleen, right testis, and thymus were weighed. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin, processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin. Complete histopathologic examinations were performed by the study laboratory pathologist on all chamber control and 400 ppm animals and 200 ppm female rats. In addition, the liver in the remaining groups of male rats, the kidney in the remaining groups of rats and mice, and the urinary bladder in the remaining groups of mice were examined. Table 1 lists the tissues and organs routinely examined.

After a review of the laboratory reports and selected histopathology slides by a quality assessment (QA) pathologist, the findings and reviewed slides were submitted to a NTP Pathologists’ Peer Review (PPR) coordinator for a second independent review. Any inconsistencies in the diagnoses made by the study laboratory and QA pathologists were resolved by the pathology peer review process. Final diagnoses for reviewed lesions represent a consensus of the PPR or a consensus between the study laboratory pathologist, NTP pathologist, QA pathologist(s), and the PPR coordinator. Details of these review procedures have been described, in part, by Maronpot and Boorman^43^ and Boorman et al.^44^

## Statistical Methods

### Calculation and Analysis of Lesion Incidences

The incidences of lesions are presented in Appendix A as the numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. The Fisher exact test,^45^ a procedure based on the overall proportion of affected animals, was used to determine significance.

### Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between exposed and control groups in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^46^ and Williams.^47,48^ Hematology, clinical chemistry, spermatid, and epididymal spermatozoal data, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley^49^ (as modified by Williams^50^) and Dunn.^51^ Jonckheere’s test^52^ was used to assess the significance of the exposure-related trends and to determine whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic exposure-related trend (Dunnett’s or Dunn’s test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey^53^ were examined by NTP personnel, and implausible values were eliminated from the analysis. Proportions of regular cycling females in each exposed group were compared to the control group using the Fisher exact test.^45^ Tests for extended periods of estrus, diestrus, metestrus, and proestrus, as well as skipped estrus and skipped diestrus were constructed based on a Markov chain model proposed by Girard and Sager.^54^ For each exposure group, a transition probability matrix was estimated for transitions among the proestrus, estrus, metestrus, and diestrus stages, with provision for extended stays within each stage as well as for skipping estrus or diestrus within a cycle. Equality of transition matrices among exposure groups and between the control group and each exposed group was tested using chi-square statistics.

## Quality Assurance Methods

The 2-week and 3-month studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations.^55^ In addition, as records from the 3-month studies were submitted to the NTP Archives, these studies were audited retrospectively by an independent quality assessment contractor. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Toxicity Study Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Toxicity Study Report.

## Genetic Toxicology

### Bacterial Mutagenicity Test Protocol

Testing was performed using a modification of the protocol reported by Zeiger et al.^56^ α-Pinene was sent to the laboratory as a coded aliquot. It was incubated with the Salmonella typhimurium tester strains TA98 and TA100 and Escherichia coli tester strain WP2 uvrA/pKM101 (analogous to S. typhimurium strain TA102) either in buffer or S9 mix (metabolic activation enzymes and cofactors from Aroclor 1254-induced male Sprague-Dawley rat liver) for 20 minutes at 37°C. Top agar supplemented with L-histidine and d-biotin was added, and the contents of the tubes were mixed and poured onto the surfaces of minimal glucose agar plates. Histidine-independent mutant colonies arising on these plates were counted following incubation for 2 days at 37°C.

Each trial consisted of triplicate plates of concurrent positive and negative controls and at least five doses of α-pinene. The high dose was 10,000 µg/plate, which induced toxicity in some trials. All trials were repeated.

In this assay, a positive response is defined as a reproducible, dose-related increase in histidine-independent (revertant) colonies in any one strain/activation combination. An equivocal response is defined as an increase in revertants that is not dose related, is not reproducible, or is not of sufficient magnitude to support a determination of mutagenicity. A negative response is obtained when no increase in revertant colonies is observed following chemical treatment. There is no minimum percentage or fold increase required for a chemical to be judged positive or weakly positive, although positive calls are typically reserved for increases in mutant colonies that are at least twofold over background.

### Mouse Peripheral Blood Micronucleus Test Protocol

A detailed discussion of this assay is presented by MacGregor et al.^57^ At the end of the 3-month toxicity study, peripheral blood samples were obtained from male and female mice. Smears were immediately prepared and fixed in absolute methanol. The methanol-fixed slides were stained with acridine orange and coded. Slides were scanned to determine the frequency of micronuclei in 2,000 normochromatic erythrocytes (NCEs) in each of five animals per exposure group. In addition, the percentage of polychromatic erythrocytes (PCEs) among a population of 1,000 erythrocytes was scored for each exposure group as a measure of bone marrow toxicity.

The results were tabulated as the mean of the pooled results from all animals within a treatment group plus or minus the standard error of the mean. The frequency of micronucleated cells among NCEs was analyzed by a statistical software package that tested for increasing trend over exposure groups with a one-tail Cochran-Armitage trend test, followed by pairwise comparisons between each exposed group and the control group. In the presence of excess binomial variation, as detected by a binomial dispersion test, the binomial variance of the Cochran-Armitage test was adjusted upward in proportion to the excess variation. In the micronucleus test, an individual trial is considered positive if the trend test P value is less than or equal to 0.025 or if the P value for any single exposed group is less than or equal to 0.025 divided by the number of exposed groups. A final call of positive for micronucleus induction is preferably based on reproducibly positive trials (as noted above). Ultimately, the final call is determined by the scientific staff after considering the results of statistical analyses, the reproducibility of any effects observed, and the magnitudes of those effects.

### Evaluation Protocol

These are the basic guidelines for arriving at an overall assay result for assays performed by the National Toxicology Program. Statistical as well as biological factors are considered. For an individual assay, the statistical procedures for data analysis have been described in the preceding protocols. There have been instances, however, in which multiple samples of a chemical were tested in the same assay, and different results were obtained among these samples and/or among laboratories. Results from more than one aliquot or from more than one laboratory are not simply combined into an overall result. Rather, all the data are critically evaluated, particularly with regard to pertinent protocol variations, in determining the weight of evidence for an overall conclusion of chemical activity in an assay. In addition to multiple aliquots, the in vitro assays have another variable that must be considered in arriving at an overall test result. In vitro assays are conducted with and without exogenous metabolic activation. Results obtained in the absence of activation are not combined with results obtained in the presence of activation; each testing condition is evaluated separately. The results presented in the Abstract of this Toxicity Study Report represent a scientific judgment of the overall evidence for activity of the chemical in an assay.