# Appendix H Sentinel Animal Program

## H.1 Methods

Rodents used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that may affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicologic evaluation of test compounds. Under this program, the disease state of the rodents is monitored via sera or feces from extra (sentinel) or exposed animals in the study rooms. These animals and the study animals are subject to identical environmental conditions. The sentinel animals come from the same production source and weanling groups as the animals used for the studies of compounds.

Blood samples were collected from each animal and allowed to clot, and the serum was separated. All samples were processed appropriately and tested in-house or sent to BioReliance Corporation (Rockville, MD) (3-month study termination samples) for determination of the presence of pathogens. The laboratory methods and agents for which testing was performed are tabulated below; the times at which samples were collected during the studies are also listed.

Blood was collected from five animals per sex per time point.

Table H-1. Laboratory Methods and Agents Tested for in the Sentinel Animal Program

| Method/Test | Time of Collection
Rats
2-week study | In-House Antibody Testing
| Mycoplasma pulmonis | Study termination
| PVM (Pneumonia virus of mice) | Study termination
| RCV/SDA (Rat coronavirus/sialodacryoadenitis virus) | Study termination
| RPV (Rat parvovirus) | Study termination
| Sendai | Study termination
13-week study | In-House Antibody Testing
| M. pulmonis | 1 week
| PVM | 1 week
| RCV/SDA | 1 week
| RPV | 1 week
| Sendai | 1 week
| ELISA
| PVM | Study termination
| RCV/SDA | Study termination
| Sendai | Study termination
| Immunofluorescence Assay
| Parvovirus | Study termination
Mice
2-week study | In-House Antibody Testing
| GDVII (Theiler’s murine encephalomyelitis virus) | Study termination
| MHV (Mouse hepatitis virus) | Study termination
| MPV (Mouse parvovirus) | Study termination
| M. pulmonis | Study termination
| PVM | Study termination
| Sendai | Study termination
13-week study | In-House Antibody Testing
| GDVII | 1 week
| MHV | 1 week
| MPV | 1 week
| M. pulmonis | 1 week
| PVM | 1 week
| Sendai | 1 week
| ELISA
| Ectromelia virus | Study termination
| EDIM (epizootic diarrhea of infant mice) | Study termination
| GDVII | Study termination
| LCM (lymphocytic choriomeningitis virus) | Study termination
| MAd-FL (Mouse adenovirus) | Study termination
| MHV | Study termination
| MMV VP2 (Mouse minute virus viral protein 2) | Study termination
| MPV VP2 (Mouse parvovirus viral protein 2) | Study termination
| PVM | Study termination
| Reovirus | Study termination
| Sendai | Study termination

## H.2 Results

All test results were negative.