# Appendix G Ingredients, Nutrient Composition, and Contaminant Levels in NTP 2000 Rat and Mouse Ration

Table G-1 Ingredients of NTP-2000 Rat and Mouse Ration

Ingredients | Percent by Weight
Ground hard winter wheat | 22.26
Ground #2 yellow shelled corn | 22.18
Wheat middlings | 15.0
Oat hulls | 8.5
Alfalfa meal (dehydrated, 17% protein) | 7.5
Purified cellulose | 5.5
Soybean meal (49% protein) | 5.0
Fish meal (60% protein) | 4.0
Corn oil (without preservatives) | 3.0
Soy oil (without preservatives) | 3.0
Dried brewer’s yeast | 1.0
Calcium carbonate (usp) | 0.9
Vitamin premix^a^ | 0.5
Mineral premix^b^ | 0.5
Calcium phosphate, dibasic (usp) | 0.4
Sodium chloride | 0.3
Choline chloride (70% choline) | 0.26
Methionine | 0.2

^a^ Wheat middlings as carrier.

^b^ Calcium carbonate as carrier.

Table G-2 Vitamins and Minerals in NTP-2000 Rat and Mouse Ration^a^

| Amount | Source
Vitamins
A | 4,000 IU | Stabilized vitamin A palmitate or acetate
D | 1,000 IU | D-activated animal sterol
K | 1.0 mg | Menadione sodium bisulfite complex
α-Tocopheryl acetate | 100 IU | –
Niacin | 23 mg | –
Folic acid | 1.1 mg | –
d-Pantothenic acid | 10 mg | d-Calcium pantothenate
Riboflavin | 3.3 mg | –
Thiamine | 4 mg | Thiamine mononitrate
B12 | 52 µg | –
Pyridoxine | 6.3 mg | Pyridoxine hydrochloride
Biotin | 0.2 mg | d-Biotin
Minerals
Magnesium | 514 mg | Magnesium oxide
Iron | 35 mg | Iron sulfate
Zinc | 12 mg | Zinc oxide
Manganese | 10 mg | Manganese oxide
Copper | 2.0 mg | Copper sulfate
Iodine | 0.2 mg | Calcium iodate
Chromium | 0.2 mg | Chromium acetate

^a^ Per kg of finished product.

Table G-3 Nutrient Composition of NTP-2000 Rat and Mouse Ration

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by weight) | 14.4 ± 0.62 | 13.7–15.3 | 5
Crude fat (% by weight) | 8.0 ± 0.21 | 7.8–8.3 | 5
Crude fiber (% by weight) | 9.3 ± 0.34 | 8.9–9.8 | 5
Ash (% by weight) | 4.7 ± 0.18 | 4.6–5.0 | 5
Amino Acids (% of total diet)
Arginine | 0.783 ± 0.070 | 0.670–0.970 | 22
Cystine | 0.220 ± 0.024 | 0.150–0.250 | 22
Glycine | 0.701 ± 0.041 | 0.620–0.800 | 22
Histidine | 0.352 ± 0.077 | 0.270–0.680 | 22
Isoleucine | 0.546 ± 0.044 | 0.430–0.660 | 22
Leucine | 1.095 ± 0.067 | 0.960–1.240 | 22
Lysine | 0.711 ± 0.114 | 0.310–0.860 | 22
Methionine | 0.409 ± 0.046 | 0.260–0.490 | 22
Phenylalanine | 0.628 ± 0.040 | 0.540–0.720 | 22
Threonine | 0.505 ± 0.043 | 0.430–0.610 | 22
Tryptophan | 0.150 ± 0.028 | 0.110–0.200 | 22
Tyrosine | 0.401 ± 0.061 | 0.280–0.540 | 22
Valine | 0.665 ± 0.043 | 0.550–0.730 | 22
Essential Fatty Acids (% of total diet)
Linoleic | 3.95 ± 0.259 | 3.49–4.55 | 22
Linolenic | 0.30 ± 0.032 | 0.21–0.35 | 22
Vitamins
Vitamin A (IU/kg) | 4,276 ± 67 | 3,230–5,080 | 5
Vitamin D (IU/kg) | 1,000^a^ | – | –
α-Tocopherol (ppm) | 80.6 ± 22.03 | 27.0–124.0 | 22
Thiamine (ppm)^b^ | 7.5 ± 0.73 | 6.6–8.6 | 5
Riboflavin (ppm) | 7.6 ± 2.89 | 4.20–17.50 | 22
Niacin (ppm) | 78.9 ± 9.08 | 66.4–98.2 | 22
Pantothenic acid (ppm) | 26.9 ± 12.63 | 17.4–81.0 | 22
Pyridoxine (ppm)^b^ | 9.54 ± 1.99 | 6.44–13.7 | 22
Folic acid (ppm) | 1.62 ± 0.48 | 1.15–3.27 | 22
Biotin (ppm) | 0.32 ± 0.10 | 0.2–0.704 | 22
Vitamin B12 (ppb) | 53.6 ± 39.6 | 18.3–174.0 | 22
Choline (ppm)^b^ | 2,846 ± 485 | 1,820–3,790 | 22
Minerals
Calcium (%) | 0.961 ± 0.045 | 0.924–1.030 | 5
Phosphorus (%) | 0.558 ± 0.018 | 0.535–0.576 | 5
Potassium (%) | 0.666 ± 0.030 | 0.626–0.733 | 22
Chloride (%) | 0.386 ± 0.039 | 0.300–0.474 | 22
Sodium (%) | 0.189 ± 0.016 | 0.160–0.222 | 22
Magnesium (%) | 0.216 ± 0.062 | 0.185–0.490 | 22
Sulfur (%) | 0.170 ± 0.029 | 0.116–0.209 | 14
Iron (ppm) | 186 ± 39.2 | 135–311 | 22
Manganese (ppm) | 51.4 ± 10.28 | 21.0–73.1 | 22
Zinc (ppm) | 53.4 ± 8.46 | 43.3–78.5 | 22
Copper (ppm) | 7.01 ± 2.562 | 3.21–16.3 | 22
Iodine (ppm) | 0.503 ± 0.206 | 0.158–0.972 | 22
Chromium (ppm) | 0.694 ± 0.276 | 0.330–1.380 | 22
Cobalt (ppm) | 0.256 ± 0.164 | 0.098–0.864 | 20

^a^ From formulation.

^b^ As hydrochloride (thiamine and pyridoxine) or chloride (choline).

Table G-4 Contaminant Levels in NTP-2000 Rat and Mouse Ration^a^

| Mean ± Standard Deviation^b^ | Range | Number of Samples
Contaminants
Arsenic (ppm) | 0.22 ± 0.036 | 0.19–0.28 | 5
Cadmium (ppm) | 0.05 ± 0.004 | 0.04–0.05 | 5
Lead (ppm) | 0.10 ± 0.020 | 0.08–0.12 | 5
Mercury (ppm) | <0.02 | – | 5
Selenium (ppm) | 0.24 ± 0.034 | 0.19–0.26 | 5
Aflatoxins (ppb) | <5.00 | – | 5
Nitrate nitrogen (ppm)^c^ | 8.60 ± 0.631 | 7.89–9.40 | 5
Nitrite nitrogen (ppm)^c^ | 3.78 ± 2.200 | 0.30–5.81 | 5
BHA (ppm)^d^ | <1.0 | – | 5
BHT (ppm)^d^ | <1.0 | – | 5
Aerobic plate count (CFU/g) | 10 ± 0 | 10 | 5
Coliform (MPN/g) | 3.0 ± 0 | 3.0 | 5
Escherichia coli (MPN/g) | <10 | – | 5
Salmonella (MPN/g) | Negative | – | 5
Total nitrosamines (ppb)^e^ | 4.8 ± 1.41 | 3.2–6.1 | 5
N-Nitrosodimethylamine (ppb)^e^ | 2.9 ± 1.20 | 3.9–1.4 | 5
N-Nitrosopyrrolidine (ppb)^e^ | 1.9 ± 0.26 | 1.5–2.2 | 5
Pesticides (ppm)
α-BHC | <0.01 | – | 5
β-BHC | <0.02 | – | 5
γ-BHC | <0.01 | – | 5
δ-BHC | <0.01 | – | 5
Heptachlor | <0.01 | – | 5
Aldrin | <0.01 | – | 5
Heptachlor epoxide | <0.01 | – | 5
DDE | <0.01 | – | 5
DDD | <0.01 | – | 5
DDT | <0.01 | – | 5
HCB | <0.01 | – | 5
Mirex | <0.01 | – | 5
Methoxychlor | <0.05 | – | 5
Dieldrin | <0.01 | – | 5
Endrin | <0.01 | – | 5
Telodrin | <0.01 | – | 5
Chlordane | <0.05 | – | 5
Toxaphene | <0.10 | – | 5
Estimated PCBs | <0.20 | – | 5
Ronnel | <0.01 | – | 5
Ethion | <0.02 | – | 5
Trithion | <0.05 | – | 5
Diazinon | <0.10 | – | 5
Methyl chlorpyrifos | 0.176 ± 0.156 | 0.025–0.356 | 5
Methyl parathion | <0.02 | – | 5
Ethyl parathion | <0.02 | – | 5
Malathion | 0.334 ± 0.094 | 0.233–0.461 | 5
Endosulfan I | <0.01 | – | 5
Endosulfan II | <0.01 | – | 5
Endosulfan sulfate | <0.03 | – | 5

^a^ Samples were irradiated. CFU = colony-forming units; MPN = most probable number; BHC = hexachlorocyclohexane or benzene hexachloride.

^b^ For values less than the limit of detection, the detection limit is given.

^c^ Sources of contamination: alfalfa, grains, and fish meal.

^d^ Sources of contamination: soy oil and fish meal.

^e^ All values were corrected for percent recovery.