# Appendix F Chemical Characterization and Generation of Chamber Concentrations

## F.1 Procurement and Characterization of α-Pinene

α-Pinene was obtained from Millennium Specialty Chemicals (Jacksonville, FL) in one lot (4KB705) that was used in the 2-week and 3-month studies. Identity and purity analyses were conducted by the study laboratory at Battelle Toxicology Northwest (Richland, WA), Chemir Analytical Services (Maryland Heights, MO), Galbraith Laboratories, Inc. (Knoxville, TN), and Huffman Laboratories, Inc. (Golden, CO). Reports on analyses performed in support of the α-pinene studies are on file at the National Institute of Environmental Health Sciences.

Lot 4KB705 of the chemical, a colorless oily liquid with a strong piney odor, was identified as α-pinene by Chemir Analytical Services using infrared (IR) and ^1^H-nuclear magnetic resonance (NMR) spectroscopy. All spectra were consistent with the literature reference spectra^82,83^ of α-pinene. Representative IR and ^1^H-NMR spectra are presented in Figure F-1 and Figure F-2, respectively.

Chemir Analytical Services determined the moisture content of lot 4KB705 using Karl Fischer titration and Galbraith Laboratories, Inc., and Huffman Laboratories, Inc., performed elemental analyses. The purity of lot 4KB705 was determined by the study laboratory using gas chromatography (GC) by systems A through D with flame ionization detection (FID) or mass spectrometry (MS) detection (Table F-1).

For lot 4KB705, Karl Fischer titration indicated a water content of 27 ppm. Elemental analyses for carbon, hydrogen, and nitrogen were in agreement with the theoretical values for α-pinene. GC/FID by system A indicated one major peak accounting for approximately 96% of the total integrated peak area and three impurity peaks with areas exceeding 0.1% of the total peak area; two of these peaks matched the retention times for prepared standards of camphene (1.77%) and β-pinene (1.73%). GC/MS by system B identified the third impurity as tricyclene (0.51%). Enantiomeric composition analysis using GC/FID system D with a chiral separation column indicated that the lot was 69% (+)-α-pinene and 31% (−)-α-pinene. The overall purity of lot 4KB705 was determined to be approximately 96%. Analysis using GC/MS by system C indicated that approximately 15 to 16 ppm butylated hydroxy toluene (BHT), a free radical scavenger, was present in the lot to prevent oxidation of α-pinene.

To ensure stability, the bulk chemical was stored at 17°C in the original shipping containers (55-gallon metal drums). Periodic reanalyses of the bulk chemical were performed during the 2-week and 3-month studies by the study laboratory using GC/MS by system B, and no degradation of the bulk chemical was detected.

## F.2 Vapor Generation and Exposure System

A diagram of the α-pinene vapor generation and delivery system used in the studies is shown in Figure F-3. The design of the system was influenced by the relatively high boiling point for α-pinene (approximately 156°C) and the need to reach relatively high concentrations. Therefore, the vapor transport lines and all dilution air were heated. α-Pinene was held in an 8-gallon stainless-steel chemical reservoir. α-Pinene was pumped through a preheater (for the 2-week studies) and into a heated glass column filled with glass beads that increased the surface area for vaporization. Heated nitrogen entered the column from below and assisted in vaporizing the chemical while conveying it into a short distribution manifold. Concentration in the manifold was determined by the chemical pump rate, nitrogen flow rate, and dilution air flow rate. The pressure in the distribution manifold was kept fixed to ensure constant flow through the manifold and into all chambers as the flow of vapor to each chamber was adjusted.

Metering valves at the manifold controlled flow to each chamber through individual Teflon^®^ delivery lines that carried the vapor from the manifold to three-way exposure valves at the chamber inlets. The exposure valves diverted vapor delivery to exposure chamber exhaust until the generation system was stable and exposures were ready to proceed. To initiate exposure, the chamber exposure valves were rotated to allow the α-pinene vapor to flow to each exposure chamber inlet duct where it was further diluted with filtered, conditioned air to achieve the desired exposure concentration.

The study laboratory designed the inhalation exposure chamber (Lab Products, Inc., Seaford, DE) so that uniform vapor concentrations could be maintained throughout the chamber with the catch pans in place. The total active mixing volume of each chamber was 1.7 m^3^. A condensation particle detector (Model 3022A, TSI, Inc., St. Paul, MN) was used with and without animals in the exposure chambers. No particle counts above the minimum resolvable level (approximately 200 particles/cm^3^) were detected.

## F.3 Vapor Concentration Monitoring

Summaries of the chamber vapor concentrations are given in Table F-2 and Table F-3. Chamber and room concentrations of α-pinene were monitored by an on-line gas chromatograph (system E, Table F-1). Samples were drawn from each exposure chamber approximately every 20 minutes during each 6-hour exposure period. A 16-port stream select valve (VALCO Instruments Company, Houston, TX) directed a continuous stream of sampled atmosphere to a six-port sampling valve (VALCO Instruments Company) with a 1.0 mL sample loop, housed in a dedicated valve oven at 175°C. A vacuum regulator maintained a constant vacuum in the sample loop to compensate for variations in sample line pressure. An in-line flow meter between the vacuum regulator and the gas chromatograph allowed digital measurement of sample flow.

The on-line gas chromatograph was checked throughout the day for instrument drift against an on-line standard vapor of α-pinene in nitrogen supplied by a standard generator (Kin-Tek; Precision Calibration Systems, La Marque, TX). The on-line gas chromatograph was recalibrated as required to meet acceptance criteria. Calibration was performed by a comparison of chamber concentration data to data from grab samples that were collected with activated coconut charcoal gas sampling tubes (ORBO™-32; Supelco, Inc., Bellefonte, PA), extracted with toluene containing butylbenzene as an internal standard, and analyzed using an off-line gas chromatograph (system F). Known volumes of chamber atmosphere were sampled at a constant flow rate ensured by a calibrated critical orifice. The off-line gas chromatograph was calibrated with gravimetrically prepared standards of α-pinene containing butylbenzene as an internal standard in toluene.

## F.4 Chamber Atmosphere Characterization

Buildup and decay rates for chamber vapor concentrations were determined with and without animals present in the chambers. At a chamber airflow rate of 15 air changes per hour, the theoretical value for the time to achieve 90% of the target concentration after the beginning of vapor generation (T_90_) and the time for the chamber concentration to decay to 10% of the target concentration after vapor generation was terminated (T_10_) was approximately 9.4 minutes. For rats and mice in the 2-week studies, T_90_ values ranged from 8 to 9 minutes with animals present and T_10_ values ranged from 9 to 10 minutes with animals present. For rats and mice in the 3-month studies, T_90_ values ranged from 8 to 9 minutes without animals present and from 9 to 12 minutes with animals; T_10_ values ranged from 8 to 10 minutes without animals present and from 9 to 10 minutes with animals. A T_90_ value of 12 minutes was selected for the 2-week studies and a T_90_ value of 10 minutes was selected for the 3-month studies.

The uniformity of vapor concentration in the inhalation exposure chambers without animals present was evaluated before the 3-month studies began; in addition, concentration uniformity with animals present in the chambers was measured once during the 2-week and 3-month studies. The vapor concentration was measured using the on-line gas chromatograph (system E, Table F-1) with the stream-selection valve fixed in one position to allow continuous monitoring from a single input line. During the studies, concentrations were measured at 12 chamber positions, one in front and one in back for each of the six possible animal cage unit positions per chamber. Chamber concentration uniformity was maintained throughout the studies.

The persistence of α-pinene in the chambers after vapor delivery ended was determined by monitoring the vapor concentration overnight in the 1,600 ppm chamber in the 2-week studies and the 400 ppm chamber in the 3-month studies. In the 2-week studies, the concentration decreased to 1% of the target concentration within 22 minutes with animals present. In the 3-month studies, the concentration decreased to 1% of the target concentration within 21 minutes with animals present and within 22 minutes without animals present.

Samples of the test atmosphere from the distribution lines and low and high exposure concentration chambers were collected at the beginning and end of one generation day during the 2-week studies and at the beginning and end of one generation day prior to the 3-month studies and one generation day during the 3-month studies. Atmosphere samples were collected with adsorbent gas sampling tubes containing activated coconut charcoal (ORBO™-32; Supelco, Inc.), followed by a tube containing silica gel (ORBO™-52; Supelco, Inc.) and extracted with methylene chloride. Additional samples were collected from the generator reservoir, and all of the samples were analyzed using GC/FID by system A (with a final temperature of 260°C for the 3-month studies) to measure the stability and purity of α-pinene in the generation and delivery system. To assess whether impurities or degradation products coeluted with α-pinene or the solvent, a second GC/FID analysis of the samples was performed using a polar column capable of resolving compounds with similar boiling points and polarities (system G; final temperature was 260°C for the 3-month studies). Analyses of BHT content and enantiomeric ratio in the generation and delivery system samples were conducted using GC/MS by system C and GC/FID by system D, respectively.

No evidence of degradation of α-pinene was noted in any part of the exposure system. Three impurity peaks with areas greater than 0.1% of the total peak area were consistently detected in atmosphere and generator reservoir samples collected during the 2-week and 3-month studies. These peaks matched the retention times for prepared standards of tricyclene, camphene, and β-pinene and had area percent values similar to those measured during the initial bulk purity analyses of the test chemical. Using the polar column, no additional impurities were detected in any of the atmosphere or generator reservoir samples collected during the studies. Values for BHT content and enantiomeric ratio in the samples were similar to those determined in the initial purity assessments of lot 4KB705.

Table F-1 Gas Chromatography Systems Used in the Inhalation Studies of α-Pinene^a^

Detection System | Column | Carrier Gas | Oven Temperature Program
System A
Flame ionization | DB-5 (J&W Scientific, Folsom, CA) or Rtx-5 (Restek, Bellefonte, PA), 30 m × 0.53 mm, 1.5-µm film thickness | Helium at 6 psi head pressure | 40°C for 3 minutes, then 4°C/minute to 300°C
System B
Mass spectrometry | DB-5, 30 m × 0.25 mm, 1.0-µm film thickness (J&W Scientific) | Helium at 6 psi head pressure | 40°C for 3 minutes, then 4°C/minute to 260°C
System C
Mass spectrometry | DB-5, 30 m × 0.25 mm, 1.0-µm film thickness (J&W Scientific) | Helium at 6 psi head pressure | 90°C for 3 minutes, then 8°C/minute to 240°C
System D
Flame ionization | CycloSil-B, 30 m × 0.25 mm, 0.25-µm film thickness (J&W Scientific) | Helium at 16 psi head pressure | 60°C for 0.5 minutes, then 5°C/minute to 105°C, then 20°C/minute to 160°C
System E
Flame ionization | DB-5, 15 m × 0.53 mm, 1.5-µm film thickness (J&W Scientific) | Nitrogen at 25 mL/minute | Isothermal at 85°C
System F
Flame ionization | DB-5, 30 m × 0.53 mm, 1.5-µm film thickness (J&W Scientific) | Helium at 6 psi head pressure | 60°C for 1 minute, then 8°C/minute to 110°C, then 15°C/minute to 200°C
System G
Flame ionization | DB-WAX, 30 m × 0.53 mm,1.0-µm film thickness (J&W Scientific) | Helium at 6 psi head pressure | 40°C for 3 minutes, then 4°C/minute to 300°C

^a^ The gas chromatographs were manufactured by Hewlett-Packard (Palo Alto, CA).

Table F-2 Summary of Chamber Concentrations in the Two-week Inhalation Studies of α-Pinene

| Target Concentration (ppm) | Total Number of Readings | Average Concentration^a^ (ppm)
Rat Chambers
| 100 | 205 | 99.6 ± 1.4
| 200 | 207 | 200 ± 1
| 400 | 206 | 404 ± 4
| 800 | 190 | 794 ± 37
| 1,600 | 16 | 1,540 ± 130
Mouse Chambers
| 100 | 223 | 99.8 ± 1.6
| 200 | 225 | 200 ± 1
| 400 | 224 | 404 ± 4
| 800 | 190 | 794 ± 37
| 1,600 | 16 | 1,540 ± 129

^a^ Mean ± standard deviation.

Table F-3 Summary of Chamber Concentrations in the Three-month Inhalation Studies of α-Pinene

| Target Concentration (ppm) | Total Number of Readings | Average Concentration^a^ (ppm)
Rat Chambers
| 25 | 1,225 | 24.9 ± 1.1
| 50 | 1,212 | 49.8 ± 0.8
| 100 | 1,227 | 99.6 ± 1.4
| 200 | 1,256 | 200 ± 5
| 400 | 1,264 | 401 ± 6
Mouse Chambers
| 25 | 1,265 | 24.9 ± 1.1
| 50 | 1,250 | 49.8 ± 0.8
| 100 | 1,265 | 99.6 ± 1.4
| 200 | 1,296 | 200 ± 4
| 400 | 1,304 | 401 ± 7

^a^ Mean ± standard deviation.

Figure F-1

Infrared Absorption Spectrum of α-Pinene

Figure F-2

^1^H-Nuclear Magnetic Resonance Spectrum of α-Pinene

Figure F-3

Schematic of the Vapor Generation and Delivery System in the Inhalation Studies of α-Pinene