# Appendix E Reproductive Tissue Evaluations and Estrous Cycle Characterization

Table E-1 Summary of Reproductive Tissue Evaluations for Male Rats in the Three-month Inhalation Study of α-Pinene^a^

| Chamber Control | | 100 ppm | 200 ppm | | 400 ppm
n | 10 | | 10 | 9 | | 10
Weights (g)
Necropsy body wt | 335 ± 6 | | 334 ± 7 | 332 ± 4 | | 322 ± 6
L. Cauda epididymis | 0.1973 ± 0.0063 | | 0.1923 ± 0.0062 | 0.1861 ± 0.0062 | | 0.1802 ± 0.0057
L. Epididymis | 0.4860 ± 0.0067 | | 0.4724 ± 0.0094 | 0.4780 ± 0.0090 | | 0.4650 ± 0.0092
L. Testis | 1.4283 ± 0.0257 | | 1.4061 ± 0.0160 | 1.4001 ± 0.0191 | | 1.4337 ± 0.0213
Spermatid measurements
Spermatid heads (10^3^/mg testis) | 129.3 ± 4.2 | | 132.8 ± 3.7 | 136.7 ± 3.1 | | 137.5 ± 3.3
Spermatid heads (10^6^/testis) | 167.5 ± 5.6 | | 163.8 ± 5.1 | 168.3 ± 4.3 | | 172.4 ± 3.5
Epididymal spermatozoal measurements
Sperm motility (%) | 91.73 ± 1.26 | | 91.40 ± 0.93 | 91.24 ± 0.80 | 90.93 ± 0.89
Sperm (10^3^/mg cauda epididymis) | 615.0 ± 34.3 | | 596.5 ± 31.8 | 526.3 ± 19.0 | 547.4 ± 14.0
Sperm (10^6^/cauda epididymis) | 120.89 ± 6.79 | | 113.16 ± 3.11 | 97.52 ± 3.51** | 98.40 ± 3.02**

** Significantly different (P ≤ 0.01) from the chamber control group by Shirley’s test.

^a^ Data are presented as mean ± standard error.

Table E-2 Estrous Cycle Characterization for Female Rats in the Three-month Inhalation Study of α-Pinene^a^

| Chamber Control | 100 ppm | 200 ppm | 400 ppm
Number weighed at necropsy | 10 | 10 | 10 | 4
Necropsy body wt (g) | 194 ± 3 | 199 ± 3 | 201 ± 3 | 159 ± 5**
Proportion of regular cycling females^b^ | 10/10 | 10/10 | 10/10 | 5/5
Estrous cycle length (days) | 5.05 ± 0.05 | 5.00 ± 0.00 | 4.90 ± 0.10 | 6.00 ± 0.32**^c^
Estrous stages^d^ (% of cycle)
Diestrus | 58.3 | 57.5 | 55.0 | 58.3
Proestrus | 17.5 | 20.0 | 15.8 | 10.0
Estrus | 20.8 | 20.8 | 20.8 | 18.3
Metestrus | 3.3 | 1.7 | 8.3 | 13.3

** Significantly different (P ≤ 0.01) from the chamber control group by Dunnett’s test (body weights) or Dunn’s test (estrous cycle length).

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error.

^b^ Number of females with a regular cycle/number of females cycling.

^c^ n = 5.

^d^ By multivariate analysis of variance, exposed females do not differ significantly from the chamber control females in the relative length of time spent in the estrous stages. Tests for equality of transition probability matrices among all groups and between the chamber control group and each exposed group indicated exposed females did not spend significantly more time in the estrous stages than did the chamber control females.

Table E-3 Results of Vaginal Cytology Study Using the Transition Matrix Approach in Female Rats Administered α-Pinene by Inhalation for Three Months

Stage | Comparison | P Value | Trend^a^
Overall tests | Overall | 0.859
Overall tests | 100 ppm vs. chamber controls | 0.917 | –
Overall tests | 200 ppm vs. chamber controls | 0.682 | N
Overall tests | 400 ppm vs. chamber controls | 0.44 | N
Extended estrus | Overall | 0.913
Extended estrus | 100 ppm vs. chamber controls | 0.354 | N
Extended estrus | 200 ppm vs. chamber controls | 1 | –
Extended estrus | 400 ppm vs. chamber controls | 1 | –
Extended diestrus | Overall | 0.704
Extended diestrus | 100 ppm vs. chamber controls | 0.561 | –
Extended diestrus | 200 ppm vs. chamber controls | 0.666 | N
Extended diestrus | 400 ppm vs. chamber controls | 0.4 | N
Extended metestrus | Overall | 1
Extended metestrus | 100 ppm vs. chamber controls | 1 | –
Extended metestrus | 200 ppm vs. chamber controls | 1 | –
Extended metestrus | 400 ppm vs. chamber controls | 1 | –
Extended proestrus | Overall | 1
Extended proestrus | 100 ppm vs. chamber controls | 1 | –
Extended proestrus | 200 ppm vs. chamber controls | 1 | –
Extended proestrus | 400 ppm vs. chamber controls | 1 | –
Skipped estrus | Overall | 1
Skipped estrus | 100 ppm vs. chamber controls | 1 | –
Skipped estrus | 200 ppm vs. chamber controls | 1 | –
Skipped estrus | 400 ppm vs. chamber controls | 1 | –
Skipped diestrus | Overall | 1
Skipped diestrus | 100 ppm vs. chamber controls | 1 | –
Skipped diestrus | 200 ppm vs. chamber controls | 1 | –
Skipped diestrus | 400 ppm vs. chamber controls | 1 | –

^a^ N means that the treated group had a lower probability of transitioning to the relevant abnormal state (extended estrus, extended diestrus, extended metestrus, extended proestrus, skipped estrus, or skipped diestrus) than did the chamber control group.

Table E-4 Summary of Reproductive Tissue Evaluations for Male Mice in the Three-month Inhalation Study of α-Pinene^a^

| Chamber Control | | 100 ppm | 200 ppm | 400 ppm
n | 10 | | 10 | 10 | 10
Weights (g)
Necropsy body wt | 37.1 ± 0.6 | | 35.9 ± 0.7 | 35.5 ± 1.0 | 36.2 ± 0.5
L. Cauda epididymis | 0.0217 ± 0.0013 | | 0.0173 ± 0.0007** | 0.0187 ± 0.0010 | 0.0198 ± 0.0008
L. Epididymis | 0.0527 ± 0.0013 | | 0.0503 ± 0.0013 | 0.0485 ± 0.0019 | 0.0489 ± 0.0021
L. Testis | 0.1144 ± 0.0021 | | 0.1102 ± 0.0026 | 0.1068 ± 0.0019* | 0.1073 ± 0.0018
Spermatid measurements
Spermatid heads (10^3^/mg testis) | 190.9 ± 9.4^b^ | | 197.8 ± 5.9^b^ | 214.5 ± 8.1* | 202.7 ± 6.4
Spermatid heads (10^6^/testis) | 19.88 ± 1.09^b^ | | 20.02 ± 0.53^b^ | 20.75 ± 0.65 | 19.48 ± 0.58
Epididymal spermatozoal measurements
Sperm motility (%) | 90.25 ± 0.34 | | 88.31 ± 0.86 | 89.74 ± 0.80 | 87.95 ± 1.08
Sperm (10^3^/mg cauda epididymis) | 704.8 ± 64.9 | | 690.7 ± 55.9 | 537.5 ± 27.0* | 445.8 ± 13.5**
Sperm (10^6^/cauda epididymis) | 24.45 ± 0.95 | | 18.40 ± 0.41** | 16.48 ± 0.72** | 14.64 ± 0.25**

* Significantly different (P ≤ 0.05) from the chamber control group by Dunnett’s test (left testis weights), Dunn’s test (spermatid heads/mg testis measurements), or Shirley’s test (sperm/mg cauda epididymis measurements).

** Significantly different (P ≤ 0.01) from the chamber control group by Dunnett’s test (left cauda epididymis weights) or Shirley’s test (sperm/mg cauda epididymis and sperm/cauda epididymis measurements).

^a^ Data are presented as mean ± standard error.

^b^ n = 9.

Table E-5 Estrous Cycle Characterization for Female Mice in the Three-month Inhalation Study of α-Pinene^a^

| Chamber Control | 100 ppm | 200 ppm | 400 ppm
Number weighed at necropsy | 10 | 10 | 10 | 10
Necropsy body wt (g) | 31.5 ± 0.6 | 31.5 ± 1.1 | 30.7 ± 0.6 | 30.6 ± 0.5
Proportion of regular cycling females^b^ | 9/10 | 8/9 | 9/10 | 8/9
Estrous cycle length (days) | 3.91 ± 0.05 | 4.04 ± 0.15^c^ | 3.96 ± 0.07 | 3.82 ± 0.11^d^
Estrous stages^e^ (% of cycle)
Diestrus | 25.0 | 32.5 | 26.7 | 27.8
Proestrus | 0.0 | 0.0 | 0.0 | 0.0
Estrus | 50.8 | 45.8 | 50.0 | 50.0
Metestrus | 24.2 | 21.7 | 23.3 | 22.2

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error.

^b^ Number of females with a regular cycle/number of females cycling.

^c^ Estrous cycle was longer than 12 days or unclear in 1 of 10 animals.

^d^ n = 9.

^e^ By multivariate analysis of variance, exposed females do not differ significantly from the chamber control females in the relative length of time spent in the estrous stages. Tests for equality of transition probability matrices among all groups and between the chamber control group and each exposed group indicated exposed females did not spend significantly more time in the estrous stages than did the chamber control females.

Table E-6 Results of Vaginal Cytology Study Using the Transition Matrix Approach in Female Mice Administered α-Pinene by Inhalation for Three Months

Stage | Comparison | P Value | Trend^a^
Overall tests | Overall | 0.12
Overall tests | 100 ppm vs. chamber controls | 0.033 | –
Overall tests | 200 ppm vs. chamber controls | 1 | –
Overall tests | 400 ppm vs. chamber controls | 0.191 | –
Extended estrus | Overall | 0.969
Extended estrus | 100 ppm vs. chamber controls | 1 | –
Extended estrus | 200 ppm vs. chamber controls | 1 | –
Extended estrus | 400 ppm vs. chamber controls | 0.509 | –
Extended diestrus | Overall | 0.994
Extended diestrus | 100 ppm vs. chamber controls | 0.703 | –
Extended diestrus | 200 ppm vs. chamber controls | 1 | –
Extended diestrus | 400 ppm vs. chamber controls | 0.995 | –
Extended metestrus | Overall | 1
Extended metestrus | 100 ppm vs. chamber controls | 1 | –
Extended metestrus | 200 ppm vs. chamber controls | 1 | –
Extended metestrus | 400 ppm vs. chamber controls | 1 | –
Extended proestrus | Overall | 1
Extended proestrus | 100 ppm vs. chamber controls | 1 | –
Extended proestrus | 200 ppm vs. chamber controls | 1 | –
Extended proestrus | 400 ppm vs. chamber controls | 1 | –
Skipped estrus | Overall | 1
Skipped estrus | 100 ppm vs. chamber controls | 1 | –
Skipped estrus | 200 ppm vs. chamber controls | 1 | –
Skipped estrus | 400 ppm vs. chamber controls | 1 | –
Skipped diestrus | Overall | 1
Skipped diestrus | 100 ppm vs. chamber controls | 1 | –
Skipped diestrus | 200 ppm vs. chamber controls | 1 | –
Skipped diestrus | 400 ppm vs. chamber controls | 1 | –
Summary of Significant Groups
Overall tests | 100 ppm vs. chamber controls | 0.033

^a^ N means that the treated group had a lower probability of transitioning to the relevant abnormal state (extended estrus, extended diestrus, extended metestrus, extended proestrus, skipped estrus, or skipped diestrus) than did the chamber control group.

Figure E-1

Individual Vaginal Cytology Plots for Female Rats in the Three-month Inhalation Study of α-Pinene

D = diestrus, P = proestrus, E = estrus, M = metestrus. Cytology is aligned based on the second estrus observation.

Figure E-2

Individual Vaginal Cytology Plots for Female Mice in the Three-month Inhalation Study of α-Pinene

D = diestrus, E = estrus, M = metestrus. Cytology is aligned based on the second estrus observation.