# Appendix D Organ Weights and Organ-Weight-to-Body Ratios

Table D-1 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the Two-week Inhalation Study of α-Pinene^a^

| Chamber Control | 100 ppm | 200 ppm | 400 ppm | 800 ppm | 1,600 ppm
n | 5 | 5 | 5 | 5 | 0^b^ | 0^b^
Male
Necropsy body wt | 172 ± 3 | 171 ± 2 | 173 ± 7 | 176 ± 4 | – | –
Heart
Absolute | 0.620 ± 0.008 | 0.614 ± 0.006 | 0.592 ± 0.028 | 0.620 ± 0.018 | – | –
Relative | 3.602 ± 0.098 | 3.584 ± 0.033 | 3.418 ± 0.039 | 3.534 ± 0.059 | – | –
R. Kidney
Absolute | 0.714 ± 0.014 | 0.758 ± 0.020 | 0.790 ± 0.044 | 0.796 ± 0.026 | – | –
Relative | 4.142 ± 0.075 | 4.425 ± 0.117* | 4.556 ± 0.098** | 4.535 ± 0.069** | – | –
Liver
Absolute | 7.988 ± 0.154 | 8.064 ± 0.196 | 8.284 ± 0.410 | 9.668 ± 0.422** | – | –
Relative | 46.331 ± 0.589 | 47.091 ± 1.287 | 47.824 ± 0.791 | 55.069 ± 1.780** | – | –
Lung
Absolute | 1.294 ± 0.119 | 1.216 ± 0.067 | 1.228 ± 0.060 | 1.566 ± 0.075 | – | –
Relative | 7.504 ± 0.660 | 7.081 ± 0.309 | 7.100 ± 0.245 | 8.971 ± 0.568 | – | –
R. Testis
Absolute | 0.994 ± 0.015 | 0.984 ± 0.016 | 0.981 ± 0.034 | 0.991 ± 0.016 | – | –
Relative | 5.770 ± 0.130 | 5.744 ± 0.064 | 5.681 ± 0.157 | 5.654 ± 0.085 | – | –
Thymus
Absolute | 0.403 ± 0.012 | 0.439 ± 0.016 | 0.427 ± 0.016 | 0.426 ± 0.007 | – | –
Relative | 2.344 ± 0.095 | 2.565 ± 0.106 | 2.477 ± 0.096 | 2.431 ± 0.037 | – | –
Female
Necropsy body wt | 125 ± 3 | 130 ± 3 | 129 ± 2 | 118 ± 2 | – | –
Heart
Absolute | 0.466 ± 0.012 | 0.484 ± 0.022 | 0.480 ± 0.008 | 0.444 ± 0.017 | – | –
Relative | 3.728 ± 0.089 | 3.727 ± 0.080 | 3.736 ± 0.073 | 3.752 ± 0.091 | – | –
R. Kidney
Absolute | 0.530 ± 0.021^c^ | 0.586 ± 0.016 | 0.602 ± 0.007* | 0.578 ± 0.017 | – | –
Relative | 4.220 ± 0.058^c^ | 4.521 ± 0.038 | 4.686 ± 0.071** | 4.896 ± 0.166** | – | –
Liver
Absolute | 4.854 ± 0.194 | 5.404 ± 0.260 | 5.764 ± 0.051** | 5.244 ± 0.138 | – | –
Relative | 38.750 ± 0.728 | 41.602 ± 1.031* | 44.888 ± 0.926** | 44.379 ± 1.012** | – | –
Lung
Absolute | 0.850 ± 0.022 | 1.066 ± 0.041** | 1.042 ± 0.046* | 0.862 ± 0.060 | – | –
Relative | 6.808 ± 0.233 | 8.221 ± 0.223* | 8.114 ± 0.371 | 7.315 ± 0.572 | – | –
Thymus
Absolute | 0.317 ± 0.003 | 0.335 ± 0.006 | 0.361 ± 0.011* | 0.285 ± 0.017 | – | –
Relative | 2.535 ± 0.052 | 2.590 ± 0.059 | 2.807 ± 0.062 | 2.413 ± 0.149 | – | –

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights). are given as mg organ weight/g body weight (mean ± standard error).

^b^ No data were available for the 800 and 1,600 ppm groups due to 100% mortality.

^c^ n = 4.

Table D-2 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the Three-month Inhalation Study of α-Pinene^a^

| Chamber Control | 25 ppm | 50 ppm | 100 ppm | 200 ppm | 400 ppm
Male
n | 10 | 10 | 10 | 10 | 10 | 10
Necropsy body wt | 335 ± 6 | 329 ± 11 | 333 ± 6 | 334 ± 7 | 330 ± 4 | 322 ± 6
Heart
Absolute | 0.918 ± 0.018 | 0.852 ± 0.029 | 0.875 ± 0.020 | 0.888 ± 0.022 | 0.855 ± 0.009 | 0.893 ± 0.019
Relative | 2.739 ± 0.036 | 2.589 ± 0.031* | 2.630 ± 0.045 | 2.659 ± 0.034 | 2.591 ± 0.032* | 2.777 ± 0.034
R. Kidney
Absolute | 1.025 ± 0.019 | 1.012 ± 0.037 | 1.061 ± 0.026 | 1.137 ± 0.027** | 1.209 ± 0.020** | 1.286 ± 0.039**
Relative | 3.058 ± 0.038 | 3.073 ± 0.037 | 3.186 ± 0.042* | 3.405 ± 0.036** | 3.660 ± 0.040** | 3.991 ± 0.056**
Liver
Absolute | 10.54 ± 0.27 | 10.31 ± 0.40 | 10.44 ± 0.32 | 11.08 ± 0.36 | 11.37 ± 0.26 | 11.87 ± 0.45*
Relative | 31.402 ± 0.375 | 31.270 ± 0.317 | 31.298 ± 0.490 | 33.152 ± 0.569* | 34.393 ± 0.531** | 36.807 ± 0.864**
Lung
Absolute | 1.690 ± 0.117 | 1.518 ± 0.063 | 1.694 ± 0.067 | 1.751 ± 0.067 | 1.678 ± 0.046 | 1.809 ± 0.081
Relative | 5.020 ± 0.279 | 4.632 ± 0.193 | 5.088 ± 0.172 | 5.260 ± 0.223 | 5.082 ± 0.129 | 5.629 ± 0.227
Spleen
Absolute | 0.628 ± 0.012 | 0.630 ± 0.013 | 0.663 ± 0.014 | 0.659 ± 0.009 | 0.655 ± 0.010 | 0.677 ± 0.023*
Relative | 1.874 ± 0.028 | 1.925 ± 0.045 | 1.997 ± 0.058 | 1.978 ± 0.030 | 1.983 ± 0.022 | 2.103 ± 0.057**
R. Testis
Absolute | 1.380 ± 0.019 | 1.303 ± 0.022 | 1.375 ± 0.019 | 1.347 ± 0.022 | 1.326 ± 0.028 | 1.378 ± 0.023
Relative | 4.121 ± 0.065 | 3.983 ± 0.090 | 4.138 ± 0.074 | 4.040 ± 0.050 | 4.013 ± 0.074 | 4.291 ± 0.079
Thymus
Absolute | 0.416 ± 0.016 | 0.384 ± 0.019 | 0.400 ± 0.018 | 0.412 ± 0.011 | 0.409 ± 0.016 | 0.369 ± 0.018
Relative | 1.241 ± 0.049 | 1.175 ± 0.068 | 1.208 ± 0.059 | 1.237 ± 0.039 | 1.237 ± 0.041 | 1.150 ± 0.054
Female
n | 10 | 10 | 10 | 10 | 10 | 4
Necropsy body wt | 194 ± 3 | 199 ± 4 | 206 ± 4 | 199 ± 3 | 201 ± 3 | 159 ± 5**
Heart
Absolute | 0.584 ± 0.010 | 0.612 ± 0.012 | 0.618 ± 0.010 | 0.629 ± 0.012* | 0.638 ± 0.011** | 0.530 ± 0.006*
Relative | 3.010 ± 0.039 | 3.081 ± 0.054 | 3.002 ± 0.041 | 3.156 ± 0.034* | 3.175 ± 0.049* | 3.349 ± 0.084**
R. Kidney
Absolute | 0.618 ± 0.011 | 0.641 ± 0.009 | 0.680 ± 0.013** | 0.659 ± 0.015 | 0.679 ± 0.014** | 0.595 ± 0.021
Relative | 3.185 ± 0.040 | 3.230 ± 0.062 | 3.301 ± 0.041 | 3.307 ± 0.058 | 3.376 ± 0.050* | 3.757 ± 0.138**
Liver
Absolute | 5.486 ± 0.179 | 5.990 ± 0.121 | 6.270 ± 0.115** | 6.269 ± 0.151** | 6.424 ± 0.144** | 4.840 ± 0.247
Relative | 28.216 ± 0.637 | 30.152 ± 0.550** | 30.438 ± 0.319** | 31.459 ± 0.586** | 31.916 ± 0.317** | 30.470 ± 0.715**
Lung
Absolute | 1.064 ± 0.014 | 1.055 ± 0.026 | 1.139 ± 0.033 | 1.205 ± 0.066 | 1.171 ± 0.056 | 1.148 ± 0.070
Relative | 5.488 ± 0.082 | 5.304 ± 0.088 | 5.524 ± 0.111 | 6.056 ± 0.343 | 5.809 ± 0.216 | 7.234 ± 0.384**
Spleen
Absolute | 0.391 ± 0.005 | 0.402 ± 0.005 | 0.411 ± 0.006 | 0.393 ± 0.006 | 0.402 ± 0.006 | 0.320 ± 0.009**
Relative | 2.017 ± 0.033 | 2.026 ± 0.034 | 1.997 ± 0.032 | 1.975 ± 0.037 | 2.001 ± 0.025 | 2.020 ± 0.047
Thymus
Absolute | 0.347 ± 0.012 | 0.349 ± 0.010 | 0.352 ± 0.010 | 0.346 ± 0.010 | 0.330 ± 0.014 | 0.204 ± 0.010**
Relative | 1.785 ± 0.054 | 1.751 ± 0.029 | 1.707 ± 0.041 | 1.739 ± 0.048 | 1.638 ± 0.058* | 1.286 ± 0.035**

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Table D-3 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Two-week Inhalation Study of α-Pinene^a^

| Chamber Control | 100 ppm | 200 ppm | 400 ppm | 800 ppm | 1,600 ppm
n | 5 | 5 | 5 | 5 | 0^b^ | 0^b^
Male
Necropsy body wt | 27.9 ± 0.7 | 26.7 ± 0.7 | 26.6 ± 0.9 | 27.0 ± 0.6 | – | –
Heart
Absolute | 0.136 ± 0.006 | 0.124 ± 0.004 | 0.126 ± 0.005 | 0.136 ± 0.008 | – | –
Relative | 4.872 ± 0.140 | 4.640 ± 0.127 | 4.743 ± 0.182 | 5.028 ± 0.223 | – | –
R. Kidney
Absolute | 0.234 ± 0.011 | 0.246 ± 0.009 | 0.236 ± 0.015 | 0.254 ± 0.012 | – | –
Relative | 8.377 ± 0.226 | 9.194 ± 0.191 | 8.832 ± 0.297 | 9.401 ± 0.337* | – | –
Liver
Absolute | 1.436 ± 0.066 | 1.394 ± 0.044 | 1.476 ± 0.069 | 1.672 ± 0.056* | – | –
Relative | 51.415 ± 1.352 | 52.117 ± 0.648 | 55.355 ± 0.721* | 61.935 ± 1.281** | – | –
Lung
Absolute | 0.184 ± 0.011 | 0.186 ± 0.007 | 0.200 ± 0.017 | 0.184 ± 0.006 | – | –
Relative | 6.579 ± 0.260 | 6.953 ± 0.154 | 7.498 ± 0.510 | 6.814 ± 0.120 | – | –
R. Testis
Absolute | 0.099 ± 0.002 | 0.095 ± 0.004 | 0.089 ± 0.010 | 0.094 ± 0.002 | – | –
Relative | 3.539 ± 0.048 | 3.536 ± 0.109 | 3.301 ± 0.287 | 3.478 ± 0.074 | – | –
Thymus
Absolute | 0.057 ± 0.007 | 0.048 ± 0.004 | 0.050 ± 0.003 | 0.049 ± 0.007 | – | –
Relative | 2.030 ± 0.192 | 1.801 ± 0.131 | 1.882 ± 0.105 | 1.831 ± 0.256 | – | –
Female
Necropsy body wt | 23.0 ± 0.4 | 23.6 ± 0.5 | 23.2 ± 0.7 | 22.6 ± 0.5 | – | –
Heart
Absolute | 0.118 ± 0.004 | 0.122 ± 0.004 | 0.120 ± 0.003 | 0.118 ± 0.002 | – | –
Relative | 5.135 ± 0.090 | 5.163 ± 0.137 | 5.165 ± 0.034 | 5.221 ± 0.137 | – | –
R. Kidney
Absolute | 0.166 ± 0.005 | 0.196 ± 0.007* | 0.184 ± 0.008 | 0.180 ± 0.006 | – | –
Relative | 7.225 ± 0.137 | 8.283 ± 0.132** | 7.919 ± 0.273 | 7.952 ± 0.234 | – | –
Liver
Absolute | 1.230 ± 0.029 | 1.300 ± 0.033 | 1.320 ± 0.065 | 1.426 ± 0.036* | – | –
Relative | 53.557 ± 0.672 | 54.996 ± 0.772 | 56.718 ± 1.676 | 63.001 ± 0.995** | – | –
Lung
Absolute | 0.182 ± 0.006 | 0.190 ± 0.005 | 0.188 ± 0.004 | 0.198 ± 0.015 | – | –
Relative | 7.932 ± 0.261 | 8.033 ± 0.085 | 8.114 ± 0.273 | 8.756 ± 0.661 | – | –
Thymus
Absolute | 0.074 ± 0.003 | 0.073 ± 0.005 | 0.068 ± 0.003 | 0.060 ± 0.004 | – | –
Relative | 3.220 ± 0.122 | 3.059 ± 0.157 | 2.913 ± 0.123 | 2.654 ± 0.114* | – | –

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights). are given as mg organ weight/g body weight (mean ± standard error).

^b^ No data were available for the 800 and 1,600 ppm groups due to 100% mortality.

Table D-4 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Three-month Inhalation Study of α-Pinene^a^

| Chamber Control | 25 ppm | 50 ppm | 100 ppm | 200 ppm | 400 ppm
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 37.1 ± 0.6 | 36.9 ± 0.7 | 38.3 ± 0.9 | 35.9 ± 0.7 | 35.5 ± 1.0 | 36.2 ± 0.5
Heart
Absolute | 0.162 ± 0.003 | 0.157 ± 0.003 | 0.170 ± 0.005 | 0.159 ± 0.003 | 0.150 ± 0.003 | 0.159 ± 0.006
Relative | 4.377 ± 0.112 | 4.267 ± 0.091 | 4.446 ± 0.138 | 4.441 ± 0.129 | 4.251 ± 0.095 | 4.386 ± 0.151
R. Kidney
Absolute | 0.330 ± 0.006 | 0.318 ± 0.009 | 0.336 ± 0.010 | 0.309 ± 0.008 | 0.295 ± 0.006* | 0.307 ± 0.007*
Relative | 8.903 ± 0.167 | 8.629 ± 0.208 | 8.793 ± 0.267 | 8.617 ± 0.205 | 8.348 ± 0.145 | 8.469 ± 0.155
Liver
Absolute | 1.617 ± 0.022 | 1.589 ± 0.028 | 1.702 ± 0.040 | 1.637 ± 0.024 | 1.660 ± 0.043 | 1.957 ± 0.057**
Relative | 43.671 ± 0.880 | 43.123 ± 0.458 | 44.487 ± 0.806 | 45.651 ± 0.678 | 46.903 ± 0.750* | 54.009 ± 1.465**
Lung
Absolute | 0.217 ± 0.004 | 0.212 ± 0.004 | 0.209 ± 0.007 | 0.234 ± 0.012 | 0.199 ± 0.004 | 0.211 ± 0.007
Relative | 5.856 ± 0.117 | 5.767 ± 0.160 | 5.484 ± 0.226 | 6.525 ± 0.342 | 5.645 ± 0.176 | 5.816 ± 0.141
Spleen
Absolute | 0.072 ± 0.002 | 0.068 ± 0.002 | 0.076 ± 0.003 | 0.070 ± 0.001 | 0.069 ± 0.002 | 0.068 ± 0.002
Relative | 1.944 ± 0.058 | 1.849 ± 0.059 | 1.991 ± 0.084 | 1.952 ± 0.041 | 1.953 ± 0.050 | 1.873 ± 0.053
R. Testis
Absolute | 0.117 ± 0.002 | 0.117 ± 0.002 | 0.116 ± 0.004 | 0.114 ± 0.002 | 0.112 ± 0.002 | 0.109 ± 0.002*
Relative | 3.167 ± 0.062 | 3.170 ± 0.079 | 3.033 ± 0.064 | 3.178 ± 0.067 | 3.173 ± 0.069 | 3.017 ± 0.058
Thymus
Absolute | 0.066 ± 0.004 | 0.063 ± 0.004 | 0.067 ± 0.003 | 0.057 ± 0.001 | 0.062 ± 0.004 | 0.051 ± 0.003**
Relative | 1.777 ± 0.081 | 1.699 ± 0.090 | 1.742 ± 0.063 | 1.591 ± 0.052 | 1.739 ± 0.115 | 1.397 ± 0.081**
Female
Necropsy body wt | 31.5 ± 0.6 | 30.3 ± 0.6 | 32.7 ± 0.7 | 31.5 ± 1.1 | 30.7 ± 0.6 | 30.6 ± 0.5
Heart
Absolute | 0.147 ± 0.002 | 0.146 ± 0.004 | 0.148 ± 0.006 | 0.157 ± 0.005 | 0.149 ± 0.004 | 0.147 ± 0.004
Relative | 4.683 ± 0.121 | 4.816 ± 0.110 | 4.528 ± 0.139 | 5.027 ± 0.170 | 4.865 ± 0.134 | 4.802 ± 0.135
R. Kidney
Absolute | 0.208 ± 0.004 | 0.207 ± 0.003 | 0.206 ± 0.004 | 0.217 ± 0.007 | 0.212 ± 0.004 | 0.210 ± 0.003
Relative | 6.620 ± 0.159 | 6.836 ± 0.122 | 6.321 ± 0.102 | 6.915 ± 0.116 | 6.913 ± 0.092 | 6.870 ± 0.132
Liver
Absolute | 1.466 ± 0.041 | 1.475 ± 0.053 | 1.442 ± 0.036 | 1.548 ± 0.053 | 1.587 ± 0.037 | 1.730 ± 0.032**
Relative | 46.542 ± 0.988 | 48.567 ± 1.239 | 44.214 ± 0.880 | 49.280 ± 0.672* | 51.728 ± 0.795** | 56.511 ± 0.705**
Lung
Absolute | 0.253 ± 0.014 | 0.248 ± 0.010 | 0.235 ± 0.015 | 0.284 ± 0.015 | 0.249 ± 0.013 | 0.249 ± 0.013
Relative | 8.057 ± 0.473 | 8.185 ± 0.337 | 7.172 ± 0.374 | 9.154 ± 0.600 | 8.159 ± 0.494 | 8.139 ± 0.413
Spleen
Absolute | 0.090 ± 0.002 | 0.090 ± 0.003 | 0.092 ± 0.002 | 0.097 ± 0.003 | 0.094 ± 0.003 | 0.094 ± 0.003
Relative | 2.862 ± 0.071 | 2.968 ± 0.084 | 2.822 ± 0.067 | 3.097 ± 0.062 | 3.075 ± 0.126 | 3.072 ± 0.099
Thymus
Absolute | 0.053 ± 0.002 | 0.059 ± 0.002 | 0.058 ± 0.002 | 0.060 ± 0.003 | 0.055 ± 0.002 | 0.054 ± 0.002
Relative | 1.692 ± 0.079 | 1.958 ± 0.076 | 1.790 ± 0.069 | 1.910 ± 0.071 | 1.794 ± 0.072 | 1.778 ± 0.076

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ test.

** Significantly different (P ≤ 0.01) from the chamber control group by Williams’ or Dunnett’s test.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).