# Appendix C Clinical Pathology Results

Table C-1 Hematology and Clinical Chemistry Data for Rats in the Three-month Inhalation Study of α-Pinene^a^

| Chamber Control | 25 ppm | 50 ppm | 100 ppm | 200 ppm | 400 ppm
Male
Hematology
n
Day 4 | 10 | 10 | 10 | 10 | 10 | 10
Day 23 | 10 | 10 | 9 | 10 | 10 | 9
Week 14 | 10 | 10 | 10 | 10 | 10 | 10
Hematocrit (spun) (%)
Day 4 | 45.6 ± 0.3 | 45.1 ± 0.6 | 46.5 ± 0.6 | 45.5 ± 0.4 | 44.8 ± 0.5 | 44.4 ± 0.4
Day 23 | 47.9 ± 0.5 | 48.0 ± 0.6 | 47.4 ± 0.4 | 47.8 ± 0.4 | 47.7 ± 0.3 | 48.6 ± 0.5
Week 14 | 49.5 ± 0.5 | 48.3 ± 0.4 | 49.0 ± 0.3 | 48.3 ± 0.7* | 47.6 ± 0.3** | 47.7 ± 0.4**
Packed cell volume (mL/dL)
Day 4 | 44.6 ± 0.4 | 44.1 ± 0.6 | 45.0 ± 0.6 | 44.2 ± 0.4 | 43.1 ± 0.3* | 43.3 ± 0.4*
Day 23 | 47.4 ± 0.4 | 47.1 ± 0.5 | 46.5 ± 0.5 | 47.2 ± 0.4 | 46.9 ± 0.4 | 48.1 ± 0.4
Week 14 | 49.9 ± 0.5 | 48.9 ± 0.4 | 49.5 ± 0.3 | 48.3 ± 0.3* | 48.0 ± 0.3** | 47.8 ± 0.6**
Hemoglobin (g/dL)
Day 4 | 13.5 ± 0.1 | 13.4 ± 0.2 | 13.7 ± 0.1 | 13.6 ± 0.2 | 13.3 ± 0.1 | 13.2 ± 0.1
Day 23 | 14.9 ± 0.1 | 14.9 ± 0.1 | 14.6 ± 0.1 | 15.0 ± 0.1 | 14.8 ± 0.1 | 15.1 ± 0.1
Week 14 | 15.7 ± 0.1 | 15.5 ± 0.1 | 15.5 ± 0.1 | 15.3 ± 0.1* | 15.0 ± 0.1** | 15.1 ± 0.2**
Erythrocytes (10^6^/μL)
Day 4 | 7.15 ± 0.09 | 7.12 ± 0.11 | 7.27 ± 0.07 | 7.26 ± 0.08 | 7.09 ± 0.07 | 7.06 ± 0.07
Day 23 | 8.06 ± 0.06 | 7.95 ± 0.07 | 7.84 ± 0.09 | 8.04 ± 0.08 | 7.92 ± 0.07 | 8.10 ± 0.06
Week 14 | 9.35 ± 0.07 | 9.09 ± 0.05 | 9.25 ± 0.06 | 8.94 ± 0.05** | 8.92 ± 0.08** | 8.86 ± 0.10**
Reticulocytes (10^3^/μL)
Day 4 | 555.1 ± 33.2 | 528.5 ± 25.8 | 576.3 ± 22.7 | 550.7 ± 22.1 | 595.2 ± 27.5 | 594.3 ± 27.2
Day 23 | 246.2 ± 4.8 | 247.5 ± 9.6 | 246.2 ± 13.4 | 239.4 ± 4.7 | 248.5 ± 12.8 | 237.0 ± 15.5
Week 14 | 198.3 ± 15.9 | 165.1 ± 12.7 | 220.8 ± 8.6^b^ | 218.1 ± 9.0 | 230.8 ± 17.1 | 238.0 ± 14.0
Nucleated erythrocytes/100 leukocytes
Day 4 | 2.40 ± 0.52 | 2.50 ± 0.65 | 1.70 ± 0.21 | 1.80 ± 0.44 | 2.00 ± 0.33 | 3.80 ± 0.71
Day 23 | 0.60 ± 0.31 | 0.40 ± 0.22 | 0.11 ± 0.11 | 0.50 ± 0.17 | 0.20 ± 0.13 | 0.11 ± 0.11
Week 14 | 0.50 ± 0.22 | 0.30 ± 0.15 | 0.60 ± 0.22 | 0.40 ± 0.22 | 0.30 ± 0.15 | 0.70 ± 0.21
Mean cell volume (fL)
Day 4 | 62.3 ± 0.3 | 62.0 ± 0.4 | 61.8 ± 0.3 | 60.9 ± 0.5 | 60.9 ± 0.4* | 61.3 ± 0.4
Day 23 | 58.8 ± 0.2 | 59.2 ± 0.4 | 59.4 ± 0.2 | 58.8 ± 0.4 | 59.3 ± 0.4 | 59.4 ± 0.3
Week 14 | 53.4 ± 0.2 | 53.9 ± 0.4 | 53.5 ± 0.3 | 54.0 ± 0.4 | 53.9 ± 0.3 | 53.9 ± 0.3
Mean cell hemoglobin (pg)
Day 4 | 18.8 ± 0.1 | 18.8 ± 0.1 | 18.9 ± 0.0 | 18.8 ± 0.1 | 18.8 ± 0.1 | 18.7 ± 0.0
Day 23 | 18.5 ± 0.1 | 18.7 ± 0.1 | 18.7 ± 0.1 | 18.6 ± 0.1 | 18.6 ± 0.1 | 18.6 ± 0.1
Week 14 | 16.9 ± 0.1 | 17.0 ± 0.1 | 16.8 ± 0.1 | 17.1 ± 0.1 | 16.9 ± 0.1 | 17.1 ± 0.1
Mean cell hemoglobin concentration (g/dL)
Day 4 | 30.2 ± 0.1 | 30.4 ± 0.2 | 30.5 ± 0.1 | 30.9 ± 0.2* | 30.9 ± 0.1** | 30.5 ± 0.1
Day 23 | 31.5 ± 0.2 | 31.7 ± 0.2 | 31.4 ± 0.2 | 31.7 ± 0.2 | 31.5 ± 0.1 | 31.4 ± 0.2
Week 14 | 31.6 ± 0.1 | 31.6 ± 0.1 | 31.4 ± 0.1 | 31.5 ± 0.1 | 31.3 ± 0.1 | 31.7 ± 0.2
Platelets (10^3^/μL)
Day 4 | 895.4 ± 12.5 | 909.1 ± 16.4 | 895.6 ± 18.2 | 865.7 ± 15.8 | 915.4 ± 20.6 | 895.2 ± 20.8
Day 23 | 795.4 ± 17.4 | 783.0 ± 23.4 | 793.0 ± 13.3 | 804.6 ± 2.7^b^ | 853.2 ± 17.9 | 825.5 ± 4.1^c^
Week 14 | 648.9 ± 5.3 | 703.3 ± 14.8** | 696.2 ± 10.9* | 663.8 ± 10.2 | 664.1 ± 14.7 | 666.3 ± 16.0
Leukocytes (10^3^/μL)
Day 4 | 9.08 ± 0.45 | 8.94 ± 0.32 | 9.75 ± 0.44 | 9.04 ± 0.72 | 7.57 ± 0.36* | 6.95 ± 0.25**
Day 23 | 6.29 ± 0.23 | 7.10 ± 0.25 | 7.44 ± 0.29 | 8.12 ± 0.42** | 7.52 ± 0.64 | 7.20 ± 0.31
Week 14 | 7.01 ± 0.36 | 6.99 ± 0.39 | 7.86 ± 0.25 | 7.34 ± 0.37 | 6.71 ± 0.40 | 6.69 ± 0.47
Segmented neutrophils (10^3^/μL)
Day 4 | 0.87 ± 0.05 | 0.93 ± 0.04 | 1.01 ± 0.08 | 1.00 ± 0.11 | 0.87 ± 0.05 | 0.90 ± 0.04
Day 23 | 0.90 ± 0.05 | 0.94 ± 0.06 | 0.97 ± 0.05^d^ | 0.97 ± 0.05 | 1.04 ± 0.05 | 0.95 ± 0.05^d^
Week 14 | 1.20 ± 0.04 | 1.26 ± 0.05 | 1.34 ± 0.05 | 1.22 ± 0.04 | 1.19 ± 0.04 | 1.20 ± 0.09
Bands (10^3^/μL)
Day 4 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Day 23 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Week 14 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/μL)
Day 4 | 7.99 ± 0.40 | 7.82 ± 0.30 | 8.39 ± 0.38 | 7.75 ± 0.61 | 6.44 ± 0.33** | 5.88 ± 0.24**
Day 23 | 5.25 ± 0.23 | 5.91 ± 0.25 | 6.38 ± 0.22^d^ | 6.89 ± 0.40* | 6.10 ± 0.57 | 6.06 ± 0.27
Week 14 | 5.36 ± 0.35 | 5.31 ± 0.39 | 6.18 ± 0.25 | 5.66 ± 0.40 | 5.12 ± 0.41 | 4.93 ± 0.38
Monocytes (10^3^/μL)
Day 4 | 0.12 ± 0.03 | 0.10 ± 0.03 | 0.26 ± 0.03* | 0.17 ± 0.03 | 0.15 ± 0.03 | 0.09 ± 0.03
Day 23 | 0.07 ± 0.02 | 0.16 ± 0.04 | 0.07 ± 0.03^d^ | 0.18 ± 0.06 | 0.31 ± 0.12 | 0.22 ± 0.07^d^
Week 14 | 0.36 ± 0.08 | 0.32 ± 0.09 | 0.23 ± 0.11 | 0.35 ± 0.08 | 0.28 ± 0.08 | 0.44 ± 0.12
Basophils (10^3^/μL)
Day 4 | 0.008 ± 0.002 | 0.006 ± 0.002 | 0.010 ± 0.003 | 0.010 ± 0.001 | 0.007 ± 0.002 | 0.004 ± 0.002
Day 23 | 0.005 ± 0.002 | 0.004 ± 0.002 | 0.004 ± 0.002^d^ | 0.011 ± 0.005 | 0.008 ± 0.003 | 0.006 ± 0.003^d^
Week 14 | 0.010 ± 0.003 | 0.007 ± 0.003 | 0.006 ± 0.003 | 0.009 ± 0.003 | 0.008 ± 0.002 | 0.006 ± 0.002
Eosinophils (10^3^/μL)
Day 4 | 0.09 ± 0.02 | 0.08 ± 0.01 | 0.09 ± 0.01 | 0.11 ± 0.01 | 0.10 ± 0.01 | 0.08 ± 0.01
Day 23 | 0.06 ± 0.01 | 0.09 ± 0.01 | 0.08 ± 0.02^d^ | 0.08 ± 0.01 | 0.05 ± 0.01 | 0.06 ± 0.01^d^
Week 14 | 0.09 ± 0.01 | 0.10 ± 0.01 | 0.11 ± 0.01 | 0.10 ± 0.01 | 0.11 ± 0.01 | 0.11 ± 0.01
Clinical Chemistry
n | 10 | 10 | 10 | 10 | 10 | 10
Urea nitrogen (mg/dL)
Day 4 | 7.5 ± 0.4 | 7.8 ± 0.4 | 7.5 ± 0.3 | 7.4 ± 0.3 | 7.0 ± 0.4 | 7.5 ± 0.4
Day 23 | 9.9 ± 0.5 | 8.9 ± 0.4 | 9.1 ± 0.2 | 9.5 ± 0.3 | 9.8 ± 0.4 | 11.4 ± 0.6
Week 14 | 12.3 ± 0.3 | 13.7 ± 0.3* | 12.8 ± 0.3 | 13.3 ± 0.2 | 13.3 ± 0.3 | 13.6 ± 0.4*
Creatinine (mg/dL)
Day 4 | 0.29 ± 0.01 | 0.26 ± 0.02 | 0.23 ± 0.02* | 0.25 ± 0.02 | 0.25 ± 0.02 | 0.24 ± 0.02
Day 23 | 0.30 ± 0.00 | 0.32 ± 0.01 | 0.32 ± 0.03 | 0.31 ± 0.01 | 0.36 ± 0.02** | 0.38 ± 0.01**
Week 14 | 0.37 ± 0.02 | 0.37 ± 0.02 | 0.37 ± 0.03 | 0.39 ± 0.02 | 0.39 ± 0.01 | 0.40 ± 0.03
Glucose (mg/dL)
Day 4 | 137 ± 3 | 134 ± 1 | 133 ± 5 | 137 ± 3 | 139 ± 6 | 130 ± 2
Day 23 | 145 ± 12 | 126 ± 7 | 134 ± 9 | 127 ± 5 | 117 ± 4 | 116 ± 5
Week 14 | 127 ± 2 | 130 ± 3 | 124 ± 2 | 129 ± 3 | 136 ± 6 | 128 ± 3
Total protein (g/dL)
Day 4 | 6.0 ± 0.0 | 6.0 ± 0.1 | 6.1 ± 0.1 | 6.0 ± 0.0 | 6.1 ± 0.1 | 6.1 ± 0.0
Day 23 | 6.5 ± 0.1 | 6.5 ± 0.1 | 6.5 ± 0.1 | 6.5 ± 0.1 | 6.8 ± 0.1** | 6.8 ± 0.1**
Week 14 | 7.4 ± 0.1 | 7.4 ± 0.1 | 7.5 ± 0.1 | 7.4 ± 0.1 | 7.5 ± 0.1 | 7.5 ± 0.0
Albumin (g/dL)
Day 4 | 4.3 ± 0.0 | 4.3 ± 0.0 | 4.3 ± 0.0 | 4.3 ± 0.0 | 4.4 ± 0.0 | 4.4 ± 0.0
Day 23 | 4.6 ± 0.0 | 4.6 ± 0.0 | 4.5 ± 0.0 | 4.5 ± 0.1 | 4.7 ± 0.0 | 4.7 ± 0.1
Week 14 | 4.9 ± 0.1 | 4.9 ± 0.0 | 4.9 ± 0.1 | 4.8 ± 0.0 | 4.9 ± 0.0 | 4.9 ± 0.0
Globulin (g/dL)
Day 4 | 1.7 ± 0.0 | 1.7 ± 0.0 | 1.8 ± 0.0 | 1.7 ± 0.0 | 1.8 ± 0.0 | 1.8 ± 0.0
Day 23 | 1.9 ± 0.0 | 2.0 ± 0.0 | 2.0 ± 0.0 | 2.0 ± 0.0 | 2.1 ± 0.0** | 2.1 ± 0.0**
Week 14 | 2.6 ± 0.0 | 2.5 ± 0.0 | 2.6 ± 0.0 | 2.5 ± 0.0 | 2.6 ± 0.0 | 2.6 ± 0.0
A/G ratio
Day 4 | 2.5 ± 0.0 | 2.5 ± 0.0 | 2.5 ± 0.0 | 2.5 ± 0.0 | 2.5 ± 0.0 | 2.4 ± 0.0
Day 23 | 2.4 ± 0.0 | 2.4 ± 0.0 | 2.3 ± 0.1 | 2.3 ± 0.0 | 2.3 ± 0.0 | 2.2 ± 0.0**
Week 14 | 1.9 ± 0.0 | 1.9 ± 0.0 | 1.9 ± 0.0 | 1.9 ± 0.0 | 1.9 ± 0.0 | 2.0 ± 0.0
Alanine aminotransferase (IU/L)
Day 4 | 57 ± 1 | 57 ± 1 | 55 ± 1 | 53 ± 1 | 55 ± 1 | 52 ± 1**
Day 23 | 41 ± 1 | 41 ± 1 | 41 ± 1 | 39 ± 2 | 38 ± 1 | 35 ± 0**
Week 14 | 85 ± 3 | 83 ± 3 | 70 ± 3** | 60 ± 2** | 56 ± 2** | 51 ± 2**
Alkaline phosphatase (IU/L)
Day 4 | 575 ± 7 | 578 ± 10 | 566 ± 10 | 566 ± 11 | 554 ± 7 | 546 ± 11*
Day 23 | 406 ± 6 | 423 ± 11 | 433 ± 9 | 407 ± 11 | 420 ± 8 | 404 ± 12
Week 14 | 223 ± 5 | 227 ± 7 | 211 ± 4 | 200 ± 3** | 204 ± 4** | 199 ± 6**
Creatine kinase (IU/L)
Day 4 | 545 ± 121 | 507 ± 42 | 430 ± 52 | 449 ± 56 | 515 ± 54 | 434 ± 44
Day 23 | 404 ± 37 | 390 ± 40 | 409 ± 66 | 393 ± 37 | 354 ± 30 | 413 ± 45
Week 14 | 171 ± 8 | 186 ± 18 | 144 ± 14 | 155 ± 13 | 150 ± 14 | 183 ± 15
Sorbitol dehydrogenase (IU/L)
Day 4 | 13 ± 1 | 14 ± 0 | 13 ± 0 | 12 ± 0* | 14 ± 1 | 13 ± 0
Day 23 | 14 ± 1 | 14 ± 1 | 16 ± 1 | 15 ± 1 | 18 ± 1** | 15 ± 1
Week 14 | 24 ± 1 | 24 ± 1 | 22 ± 1 | 22 ± 1 | 21 ± 1* | 20 ± 1**
Bile acids (µmol/L)
Day 4 | 4.7 ± 0.4 | 4.7 ± 0.5 | 5.6 ± 0.8 | 4.6 ± 0.4 | 7.2 ± 1.3 | 4.6 ± 0.7
Day 23 | 5.7 ± 0.9 | 3.3 ± 0.2** | 4.9 ± 0.6* | 3.6 ± 0.3** | 3.8 ± 0.3** | 3.6 ± 0.7**
Week 14 | 3.3 ± 0.1 | 3.5 ± 0.4 | 3.4 ± 0.3 | 3.2 ± 0.1 | 3.8 ± 0.6 | 3.0 ± 0.1
Female
Hematology
n
Day 4 | 10 | 10 | 9 | 10 | 9 | 10
Day 23 | 10 | 10 | 10 | 9 | 10 | 9
Week 14 | 10 | 10 | 10 | 10 | 10 | 4
Hematocrit (spun) (%)
Day 4 | 47.7 ± 0.4 | 47.0 ± 0.2 | 46.6 ± 0.3 | 47.5 ± 0.3 | 47.1 ± 0.6 | 46.2 ± 0.4
Day 23 | 48.7 ± 0.4 | 49.2 ± 0.5 | 49.1 ± 0.4 | 49.2 ± 0.3 | 48.9 ± 0.5 | 49.7 ± 0.6
Week 14 | 48.9 ± 0.4 | 47.2 ± 0.4* | 47.8 ± 0.2 | 48.3 ± 0.4 | 48.7 ± 0.4 | 50.9 ± 0.8
Packed cell volume (mL/dL)
Day 4 | 46.7 ± 0.5 | 46.1 ± 0.3 | 46.0 ± 0.3 | 46.8 ± 0.4 | 46.1 ± 0.5 | 45.3 ± 0.5
Day 23 | 48.5 ± 0.4 | 49.0 ± 0.4 | 49.3 ± 0.3 | 49.2 ± 0.3 | 48.8 ± 0.3 | 50.0 ± 0.6*
Week 14 | 49.1 ± 0.3 | 48.6 ± 0.3 | 48.7 ± 0.3 | 49.0 ± 0.5 | 49.7 ± 0.4 | 52.7 ± 0.4
Hemoglobin (g/dL)
Day 4 | 14.3 ± 0.1 | 14.2 ± 0.1 | 14.2 ± 0.1 | 14.5 ± 0.1 | 14.3 ± 0.2 | 14.1 ± 0.1
Day 23 | 15.3 ± 0.1 | 15.5 ± 0.1 | 15.5 ± 0.1 | 15.5 ± 0.1 | 15.3 ± 0.1 | 15.7 ± 0.2
Week 14 | 15.7 ± 0.1 | 15.4 ± 0.1 | 15.5 ± 0.1 | 15.6 ± 0.1 | 15.8 ± 0.1 | 16.7 ± 0.2
Erythrocytes (10^6^/μL)
Day 4 | 7.64 ± 0.07 | 7.56 ± 0.05 | 7.56 ± 0.05 | 7.74 ± 0.07 | 7.67 ± 0.10 | 7.55 ± 0.08
Day 23 | 8.13 ± 0.08 | 8.13 ± 0.08 | 8.20 ± 0.07 | 8.24 ± 0.05 | 8.13 ± 0.06 | 8.31 ± 0.09
Week 14 | 8.67 ± 0.06 | 8.53 ± 0.05 | 8.54 ± 0.06 | 8.62 ± 0.09 | 8.71 ± 0.06 | 9.23 ± 0.09
Reticulocytes (10^3^/μL)
Day 4 | 402.3 ± 27.2 | 360.7 ± 22.5 | 384.6 ± 24.4 | 393.6 ± 29.7 | 392.2 ± 24.4 | 361.1 ± 13.7
Day 23 | 228.6 ± 13.4 | 219.3 ± 14.2 | 211.5 ± 9.3 | 210.1 ± 13.4 | 212.2 ± 8.2 | 227.8 ± 14.6
Week 14 | 197.6 ± 11.2 | 183.5 ± 7.7 | 176.0 ± 15.9 | 160.4 ± 13.9 | 200.3 ± 6.5 | 163.5 ± 24.4
Nucleated erythrocytes/100 leukocytes
Day 4 | 0.90 ± 0.31 | 0.40 ± 0.31 | 0.67 ± 0.24 | 0.70 ± 0.21 | 0.67 ± 0.24 | 1.00 ± 0.26
Day 23 | 0.50 ± 0.22 | 0.30 ± 0.15 | 0.70 ± 0.26 | 0.33 ± 0.24 | 0.40 ± 0.16 | 0.00 ± 0.00
Week 14 | 0.70 ± 0.30 | 0.30 ± 0.21 | 0.40 ± 0.16 | 0.20 ± 0.13 | 0.40 ± 0.22 | 0.00 ± 0.00
Mean cell volume (fL)
Day 4 | 61.1 ± 0.3 | 60.9 ± 0.3 | 60.9 ± 0.2 | 60.5 ± 0.3 | 60.2 ± 0.5 | 60.0 ± 0.3*
Day 23 | 59.6 ± 0.3 | 60.3 ± 0.3 | 60.1 ± 0.3 | 59.7 ± 0.3 | 60.1 ± 0.3 | 60.2 ± 0.2
Week 14 | 56.6 ± 0.2 | 56.9 ± 0.1 | 57.0 ± 0.1 | 56.9 ± 0.1 | 57.0 ± 0.2 | 57.1 ± 0.3
Mean cell hemoglobin (pg)
Day 4 | 18.7 ± 0.1 | 18.8 ± 0.1 | 18.8 ± 0.1 | 18.7 ± 0.1 | 18.7 ± 0.1 | 18.7 ± 0.1
Day 23 | 18.8 ± 0.1 | 19.0 ± 0.1 | 18.9 ± 0.1 | 18.8 ± 0.1 | 18.8 ± 0.1 | 18.9 ± 0.1
Week 14 | 18.1 ± 0.0 | 18.1 ± 0.1 | 18.2 ± 0.1 | 18.1 ± 0.1 | 18.1 ± 0.0 | 18.1 ± 0.0
Mean cell hemoglobin concentration (g/dL)
Day 4 | 30.6 ± 0.2 | 30.8 ± 0.1 | 30.8 ± 0.1 | 31.0 ± 0.2 | 31.1 ± 0.2 | 31.2 ± 0.2
Day 23 | 31.6 ± 0.2 | 31.5 ± 0.1 | 31.4 ± 0.1 | 31.6 ± 0.1 | 31.4 ± 0.1 | 31.4 ± 0.1
Week 14 | 32.1 ± 0.1 | 31.8 ± 0.1 | 31.9 ± 0.1 | 31.9 ± 0.1 | 31.8 ± 0.1 | 31.7 ± 0.2
Platelets (10^3^/μL)
Day 4 | 820.1 ± 18.0 | 831.2 ± 19.1 | 837.7 ± 22.6 | 797.5 ± 26.6 | 777.3 ± 23.1 | 845.4 ± 25.2
Day 23 | 764.7 ± 15.4 | 750.2 ± 11.8 | 738.4 ± 16.7 | 753.3 ± 10.1 | 778.8 ± 10.3 | 789.7 ± 15.9
Week 14 | 689.3 ± 7.2 | 660.9 ± 11.1* | 665.4 ± 16.6* | 664.1 ± 8.9* | 649.0 ± 4.6**^b^ | 580.0 ± 31.5**
Leukocytes (10^3^/μL)
Day 4 | 10.52 ± 0.52 | 10.89 ± 0.26 | 10.25 ± 0.34 | 11.26 ± 0.61 | 10.39 ± 0.63 | 8.52 ± 0.68
Day 23 | 7.96 ± 0.36 | 8.01 ± 0.24 | 7.87 ± 0.43 | 8.04 ± 0.39 | 7.78 ± 0.56 | 6.84 ± 0.48
Week 14 | 5.86 ± 0.27 | 5.70 ± 0.24 | 6.05 ± 0.29 | 5.60 ± 0.29 | 5.22 ± 0.33 | 6.08 ± 0.58
Segmented neutrophils (10^3^/μL)
Day 4 | 0.89 ± 0.02 | 0.95 ± 0.04 | 0.99 ± 0.07 | 1.19 ± 0.07** | 1.07 ± 0.11^d^ | 0.92 ± 0.08
Day 23 | 0.97 ± 0.05 | 0.88 ± 0.04 | 0.83 ± 0.04 | 0.88 ± 0.07 | 0.93 ± 0.08 | 0.80 ± 0.07*
Week 14 | 0.93 ± 0.08 | 0.90 ± 0.07 | 1.02 ± 0.10 | 0.83 ± 0.06 | 0.84 ± 0.07 | 0.80 ± 0.14
Bands (10^3^/μL)
Day 4 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Day 23 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Week 14 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/μL)
Day 4 | 9.34 ± 0.52 | 9.58 ± 0.25 | 8.90 ± 0.30 | 9.76 ± 0.59 | 9.19 ± 0.51^d^ | 7.34 ± 0.62
Day 23 | 6.79 ± 0.35 | 6.86 ± 0.20 | 6.83 ± 0.41 | 6.96 ± 0.38 | 6.62 ± 0.54 | 5.83 ± 0.42
Week 14 | 4.67 ± 0.24 | 4.44 ± 0.25 | 4.67 ± 0.23 | 4.36 ± 0.28 | 4.17 ± 0.29 | 4.93 ± 0.53
Monocytes (10^3^/μL)
Day 4 | 0.17 ± 0.04 | 0.23 ± 0.04 | 0.24 ± 0.06 | 0.17 ± 0.07 | 0.11 ± 0.04 | 0.11 ± 0.02
Day 23 | 0.10 ± 0.03 | 0.17 ± 0.02 | 0.11 ± 0.02 | 0.10 ± 0.04 | 0.13 ± 0.03 | 0.11 ± 0.02
Week 14 | 0.19 ± 0.06 | 0.28 ± 0.05 | 0.27 ± 0.05 | 0.33 ± 0.06 | 0.14 ± 0.04 | 0.27 ± 0.10
Basophils (10^3^/μL)
Day 4 | 0.013 ± 0.002 | 0.014 ± 0.002 | 0.009 ± 0.003 | 0.013 ± 0.004 | 0.008 ± 0.001 | 0.015 ± 0.005
Day 23 | 0.009 ± 0.003 | 0.011 ± 0.002 | 0.011 ± 0.003 | 0.006 ± 0.002 | 0.005 ± 0.002 | 0.006 ± 0.002
Week 14 | 0.003 ± 0.002 | 0.005 ± 0.002 | 0.004 ± 0.002 | 0.005 ± 0.002 | 0.002 ± 0.001 | 0.005 ± 0.003
Eosinophils (10^3^/μL)
Day 4 | 0.11 ± 0.01 | 0.13 ± 0.01 | 0.11 ± 0.01 | 0.13 ± 0.02 | 0.15 ± 0.02 | 0.14 ± 0.02
Day 23 | 0.10 ± 0.01 | 0.09 ± 0.01 | 0.10 ± 0.01 | 0.09 ± 0.01 | 0.10 ± 0.02 | 0.09 ± 0.01
Week 14 | 0.08 ± 0.01 | 0.07 ± 0.01 | 0.08 ± 0.01 | 0.08 ± 0.01 | 0.08 ± 0.01 | 0.07 ± 0.01
Clinical Chemistry
n
Day 4 | 10 | 10 | 10 | 10 | 10 | 10
Day 23 | 10 | 10 | 10 | 10 | 10 | 9
Week 14 | 10 | 10 | 10 | 10 | 10 | 4
Urea nitrogen (mg/dL)
Day 4 | 7.8 ± 0.4 | 8.5 ± 0.3 | 8.1 ± 0.3 | 8.3 ± 0.4 | 9.1 ± 0.3* | 8.6 ± 0.3
Day 23 | 11.5 ± 0.3 | 11.8 ± 0.4 | 11.5 ± 0.4 | 10.6 ± 0.4 | 10.8 ± 0.3 | 9.1 ± 0.4**
Week 14 | 14.1 ± 0.4 | 14.4 ± 0.4 | 13.0 ± 0.5 | 13.6 ± 0.5 | 13.4 ± 0.5 | 11.3 ± 0.5*
Creatinine (mg/dL)
Day 4 | 0.29 ± 0.01 | 0.28 ± 0.01 | 0.29 ± 0.02 | 0.26 ± 0.02 | 0.28 ± 0.01 | 0.26 ± 0.02
Day 23 | 0.31 ± 0.01 | 0.30 ± 0.00 | 0.28 ± 0.01 | 0.30 ± 0.00 | 0.30 ± 0.00 | 0.31 ± 0.01
Week 14 | 0.37 ± 0.02 | 0.35 ± 0.02 | 0.36 ± 0.02 | 0.38 ± 0.01 | 0.34 ± 0.02 | 0.35 ± 0.03
Glucose (mg/dL)
Day 4 | 138 ± 2 | 135 ± 2 | 136 ± 4 | 136 ± 2 | 139 ± 5 | 130 ± 2
Day 23 | 127 ± 3 | 123 ± 6 | 133 ± 5 | 123 ± 3 | 122 ± 3 | 122 ± 5
Week 14 | 141 ± 8 | 131 ± 5 | 123 ± 2 | 133 ± 3 | 131 ± 4 | 114 ± 12
Total protein (g/dL)
Day 4 | 5.9 ± 0.0 | 6.0 ± 0.1 | 6.1 ± 0.0 | 6.0 ± 0.0 | 6.1 ± 0.1* | 6.1 ± 0.0
Day 23 | 6.3 ± 0.1 | 6.4 ± 0.1 | 6.4 ± 0.1 | 6.5 ± 0.1 | 6.5 ± 0.1 | 6.6 ± 0.1
Week 14 | 7.5 ± 0.1 | 7.4 ± 0.1 | 7.5 ± 0.1 | 7.6 ± 0.1 | 7.5 ± 0.1 | 7.2 ± 0.1
Albumin (g/dL)
Day 4 | 4.3 ± 0.0 | 4.4 ± 0.0 | 4.4 ± 0.0 | 4.4 ± 0.0 | 4.4 ± 0.0 | 4.4 ± 0.0
Day 23 | 4.5 ± 0.0 | 4.6 ± 0.0 | 4.6 ± 0.0 | 4.6 ± 0.1 | 4.6 ± 0.0 | 4.7 ± 0.1
Week 14 | 5.2 ± 0.1 | 5.2 ± 0.1 | 5.2 ± 0.1 | 5.3 ± 0.0 | 5.2 ± 0.0 | 5.0 ± 0.1
Globulin (g/dL)
Day 4 | 1.6 ± 0.0 | 1.6 ± 0.0 | 1.6 ± 0.0 | 1.7 ± 0.0 | 1.7 ± 0.0* | 1.6 ± 0.0
Day 23 | 1.8 ± 0.0 | 1.8 ± 0.0 | 1.8 ± 0.0 | 1.9 ± 0.0* | 1.9 ± 0.0* | 2.0 ± 0.0**
Week 14 | 2.3 ± 0.1 | 2.2 ± 0.0 | 2.3 ± 0.0 | 2.3 ± 0.0 | 2.4 ± 0.0 | 2.2 ± 0.1
A/G ratio
Day 4 | 2.8 ± 0.0 | 2.7 ± 0.1 | 2.7 ± 0.0 | 2.7 ± 0.1 | 2.6 ± 0.1 | 2.7 ± 0.0
Day 23 | 2.6 ± 0.0 | 2.5 ± 0.0 | 2.5 ± 0.0 | 2.4 ± 0.0 | 2.5 ± 0.0 | 2.4 ± 0.0**
Week 14 | 2.3 ± 0.1 | 2.4 ± 0.0 | 2.3 ± 0.0 | 2.3 ± 0.0 | 2.2 ± 0.0 | 2.4 ± 0.1
Alanine aminotransferase (IU/L)
Day 4 | 47 ± 1 | 49 ± 1 | 49 ± 1 | 46 ± 1 | 45 ± 1 | 44 ± 2
Day 23 | 35 ± 1 | 36 ± 1 | 35 ± 1 | 36 ± 1 | 34 ± 1 | 31 ± 1
Week 14 | 69 ± 4 | 65 ± 5 | 55 ± 3** | 56 ± 4* | 47 ± 2** | 49 ± 5**
Alkaline phosphatase (IU/L)
Day 4 | 487 ± 8 | 493 ± 10 | 475 ± 6 | 468 ± 7 | 454 ± 5** | 457 ± 8**
Day 23 | 305 ± 5 | 311 ± 8 | 304 ± 5 | 302 ± 8 | 289 ± 8 | 289 ± 7
Week 14 | 197 ± 6 | 182 ± 4 | 182 ± 8 | 177 ± 8** | 181 ± 5* | 164 ± 13*
Creatine kinase (IU/L)
Day 4 | 364 ± 20^b^ | 332 ± 27 | 388 ± 29^b^ | 443 ± 74 | 460 ± 39^b^ | 375 ± 48
Day 23 | 299 ± 30 | 305 ± 27 | 292 ± 41 | 369 ± 43 | 338 ± 26 | 250 ± 16
Week 14 | 162 ± 16 | 165 ± 38 | 172 ± 22 | 139 ± 14 | 170 ± 22 | 145 ± 26
Sorbitol dehydrogenase (IU/L)
Day 4 | 13 ± 1 | 13 ± 0 | 14 ± 0 | 12 ± 0* | 11 ± 1* | 12 ± 0*
Day 23 | 14 ± 0 | 15 ± 1 | 15 ± 1 | 15 ± 1 | 14 ± 1 | 16 ± 0
Week 14 | 21 ± 1 | 20 ± 1 | 18 ± 1 | 17 ± 1 | 17 ± 1 | 18 ± 1
Bile acids (µmol/L)
Day 4 | 5.3 ± 0.5 | 5.0 ± 0.5 | 6.5 ± 1.1 | 5.8 ± 0.6 | 6.8 ± 1.3 | 4.9 ± 0.5
Day 23 | 4.0 ± 0.3 | 4.7 ± 0.4 | 5.4 ± 0.7 | 4.5 ± 0.4 | 3.9 ± 0.4 | 4.0 ± 0.7
Week 14 | 9.1 ± 2.3 | 4.9 ± 0.5** | 4.7 ± 0.4** | 4.3 ± 0.3** | 5.1 ± 1.1** | 16.9 ± 4.7*

* Significantly different (P ≤ 0.05) from the chamber control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.

^b^ n = 9.

^c^ n = 8.

^d^ n = 10.

Table C-2 Hematology Data for Mice in the Three-month Inhalation Study of α-Pinene^a^

| Chamber Control | 25 ppm | 50 ppm | 100 ppm | 200 ppm | 400 ppm
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Hematocrit (spun) (%) | 51.3 ± 0.3 | 50.5 ± 0.4 | 50.1 ± 0.3 | 51.1 ± 0.3 | 50.9 ± 0.4 | 49.8 ± 0.3*
Packed cell volume (mL/dL) | 51.8 ± 0.2 | 51.6 ± 0.3 | 50.7 ± 0.4 | 52.1 ± 0.4 | 52.2 ± 0.4 | 51.1 ± 0.4
Hemoglobin (g/dL) | 16.0 ± 0.1 | 16.0 ± 0.1 | 15.7 ± 0.1 | 16.0 ± 0.0 | 16.1 ± 0.1 | 15.7 ± 0.1
Erythrocytes (10^6^/µL) | 10.51 ± 0.06 | 10.47 ± 0.06 | 10.23 ± 0.09 | 10.52 ± 0.04 | 10.55 ± 0.08 | 10.10 ± 0.07**
Reticulocytes (10^3^/µL) | 223.7 ± 19.4 | 200.3 ± 14.9 | 193.9 ± 16.4 | 205.2 ± 13.0 | 214.3 ± 16.4 | 202.2 ± 15.9
Nucleated erythrocytes /100 leukocytes | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Mean cell volume (fL) | 49.3 ± 0.3 | 49.2 ± 0.2 | 49.6 ± 0.2 | 49.4 ± 0.2 | 49.6 ± 0.2 | 50.6 ± 0.2**
Mean cell hemoglobin (pg) | 15.3 ± 0.1 | 15.2 ± 0.1 | 15.4 ± 0.1 | 15.2 ± 0.0 | 15.2 ± 0.0 | 15.6 ± 0.1*
Mean cell hemoglobin concentration (g/dL) | 31.0 ± 0.2 | 31.0 ± 0.1 | 31.0 ± 0.1 | 30.8 ± 0.2 | 30.7 ± 0.1 | 30.8 ± 0.1
Platelets (10^3^/µL) | 859.7 ± 23.1 | 863.1 ± 15.5 | 853.1 ± 18.3 | 864.3 ± 28.1 | 872.4 ± 22.9 | 895.9 ± 19.9
Leukocytes (10^3^/µL) | 3.10 ± 0.40 | 2.94 ± 0.43 | 2.03 ± 0.26 | 2.47 ± 0.15 | 2.31 ± 0.26 | 1.87 ± 0.17*
Segmented neutrophils (10^3^/µL) | 0.42 ± 0.07 | 0.47 ± 0.06 | 0.21 ± 0.02* | 0.37 ± 0.05 | 0.32 ± 0.04 | 0.29 ± 0.02
Bands (10^3^/µL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/µL) | 2.60 ± 0.34 | 2.41 ± 0.39 | 1.73 ± 0.23 | 2.03 ± 0.13 | 1.93 ± 0.22 | 1.48 ± 0.14*
Monocytes (10^3^/µL) | 0.03 ± 0.01 | 0.02 ± 0.00 | 0.06 ± 0.02 | 0.04 ± 0.01 | 0.03 ± 0.02 | 0.08 ± 0.02
Basophils (10^3^/µL) | 0.020 ± 0.006 | 0.010 ± 0.003 | 0.014 ± 0.003 | 0.010 ± 0.003 | 0.008 ± 0.001 | 0.011 ± 0.003
Eosinophils (10^3^/µL) | 0.03 ± 0.01 | 0.03 ± 0.00 | 0.02 ± 0.00 | 0.02 ± 0.00 | 0.02 ± 0.00 | 0.02 ± 0.00
Howell-Jolly bodies (% erythrocytes) | 0.10 ± 0.0 | 0.2 ± 0.0 | 0.1 ± 0.0 | 0.1 ± 0.0 | 0.1 ± 0.0 | 0.1 ± 0.0
Female
Hematocrit (spun) (%) | 49.6 ± 0.3 | 50.1 ± 0.4 | 49.4 ± 0.5 | 50.1 ± 0.3 | 48.9 ± 0.3 | 48.3 ± 0.3*
Packed cell volume (mL/dL) | 50.3 ± 0.2 | 50.9 ± 0.4 | 50.0 ± 0.6 | 50.9 ± 0.3 | 49.5 ± 0.3 | 49.0 ± 0.3*
Hemoglobin (g/dL) | 15.8 ± 0.1 | 16.0 ± 0.1 | 15.7 ± 0.2 | 15.9 ± 0.1 | 15.5 ± 0.1 | 15.5 ± 0.1*
Erythrocytes (10^6^/µL) | 10.21 ± 0.05 | 10.26 ± 0.06 | 10.10 ± 0.11 | 10.14 ± 0.06 | 9.96 ± 0.09* | 9.85 ± 0.08**
Reticulocytes (10^3^/µL) | 269.5 ± 15.4 | 248.9 ± 14.9 | 251.9 ± 16.5 | 282.5 ± 18.3 | 240.1 ± 20.8 | 251.2 ± 15.3
Nucleated erythrocytes /100 leukocytes | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Mean cell volume (fL) | 49.3 ± 0.2 | 49.7 ± 0.2 | 49.5 ± 0.3 | 50.1 ± 0.2* | 49.7 ± 0.2 | 49.7 ± 0.2
Mean cell hemoglobin (pg) | 15.5 ± 0.1 | 15.6 ± 0.1 | 15.5 ± 0.1 | 15.6 ± 0.1 | 15.6 ± 0.1 | 15.7 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 31.5 ± 0.2 | 31.4 ± 0.1 | 31.4 ± 0.2 | 31.1 ± 0.1 | 31.4 ± 0.1 | 31.6 ± 0.1
Platelets (10^3^/µL) | 772.3 ± 13.7 | 773.5 ± 22.8 | 771.2 ± 17.4 | 738.3 ± 29.9 | 800.4 ± 18.1 | 827.7 ± 15.2
Leukocytes (10^3^/µL) | 3.65 ± 0.35 | 3.10 ± 0.27 | 3.34 ± 0.32 | 2.80 ± 0.29 | 3.11 ± 0.32 | 3.16 ± 0.34
Segmented neutrophils (10^3^/µL) | 0.46 ± 0.05 | 0.35 ± 0.05 | 0.45 ± 0.04 | 0.31 ± 0.05 | 0.41 ± 0.06 | 0.38± 0.06
Bands (10^3^/µL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Lymphocytes (10^3^/µL) | 3.09 ± 0.30 | 2.65 ± 0.23 | 2.78 ± 0.30 | 2.39 ± 0.25 | 2.60 ± 0.26 | 2.66 ± 0.27
Monocytes (10^3^/µL) | 0.04 ± 0.01 | 0.06 ± 0.02 | 0.05 ± 0.01 | 0.05 ± 0.02 | 0.05 ± 0.01 | 0.07 ± 0.02
Basophils (10^3^/µL) | 0.019 ± 0.007 | 0.015 ± 0.003 | 0.019 ± 0.003 | 0.019 ± 0.005 | 0.017 ± 0.005 | 0.014 ± 0.003
Eosinophils (10^3^/µL) | 0.04 ± 0.01 | 0.04 ± 0.01 | 0.04 ± 0.01 | 0.03 ± 0.01 | 0.03 ± 0.01 | 0.04 ± 0.01
Howell-Jolly bodies (% erythrocytes) | 0.2 ± 0.0 | 0.2 ± 0.0 | 0.1 ± 0.0 | 0.2 ± 0.0 | 0.2 ± 0.0 | 0.1 ± 0.0

* Significantly different (P ≤ 0.05) from the chamber control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.