# Appendix B Genetic Toxicology

Table B-1 Mutagenicity of α-Pinene in Bacterial Tester Strains^a^

Strain | Dose (μg/plate) | Without S9 | | | Without S9 | Without S9 | With 10% Rat S9 | With 10% Rat S9
TA100
| 0 | 49 ± 2 | | | 57 ± 7 | 38 ± 4 | 70 ± 2 | 63 ± 4
| 5 | | | | 48 ± 2 | | 123 ± 3 | 127 ± 6
| 10 | 46 ± 5 | | | 49 ± 4 | 45 ± 6
| 25 | | | | 52 ± 2
| 50 | 44 ± 4 | | | 29 ± 3 | 41 ± 13 | 65 ± 5 | 57 ± 5
| 75 | | | | 14 ± 1
| 100 | 63 ± 5 | | | | 54 ± 15 | 80 ± 1 | 85 ± 15
| 200 | 57 ± 4
| 250 | | | | | 19 ± 6
| 400 | 10 ± 1
| 500 | | | | | 12 ± 4 | 63 ± 6 | 48 ± 4
| 1,000 | | | | | | 58 ± 11 | 39 ± 3
| 5,000 | | | | | | 33 ± 3 | 90 ± 4
Trial summary | | Negative | | | Negative | Negative | Negative | Negative
Positive control^b^ | | 428 ± 39 | | | 387 ± 19 | 574 ± 1 | 738 ± 31 | 1,161 ± 65
| | With 10% Rat S9 | | | With 10% Rat S9
TA100
| 0 | 56 ± 2 | | | 48 ± 10
| 50 | | | | 50 ± 7
| 100 | | | | 40 ± 4
| 500 | 49 ± 4 | | | 52 ± 6
| 1,000 | | | | 38 ± 2
| 1,500 | 46 ± 2
| 2,500 | 50 ± 2
| 5,000 | 21 ± 1 | | | 27 ± 2^c^
| 10,000 | 11 ± 1
Trial summary | | Negative | | | Negative
Positive control | | 665 ± 29 | | | 510 ± 27
TA98
| 0 | 22 ± 3 | | | 15 ± 3 | 21 ± 2 | 30 ± 4 | 28 ± 5
| 5 | | | | 10 ± 3 | 23 ± 3
| 10 | 25 ± 3 | | | 9 ± 1 | 19 ± 4
| 20 | | | | 8 ± 3
| 25 | | | | | 18 ± 0
| 30 | | | | 6 ± 1
| 40 | | | | 4 ± 1^d^
| 50 | 8 ± 2^c^ | | | | 18 ± 3 | | 20 ± 3
| 75 | | | | | 9 ± 2
| 100 | 15 ± 2^c^ | | | | | | 31 ± 3
| 250 | 4 ± 1^c^
| 500 | Toxic | | | | | 32 ± 1 | 25 ± 2
| 1,000 | | | | | | | 28 ± 5
| 1,500 | | | | | | 24 ± 5
| 2,500 | | | | | | 21 ± 1
| 5,000 | | | | | | 13 ± 3 | 15 ± 1^c^
| 10,000 | | | | | | 9 ± 1
Trial summary | | Negative | | | Negative | Negative | Negative | Negative
Positive control | | 468 ± 17 | | | 506 ± 17 | 295 ± 14 | 418 ± 22 | 1,008 ± 32
| | With 10% Rat S9
TA98 (continued)
| 0 | 22 ± 2
| 50 | 22 ± 1
| 100 | 21 ± 3
| 500 | 19 ± 2
| 1,000 | 35 ± 3
| 5,000 | 7 ± 1
Trial summary | | Negative
Positive control | | 372 ± 38
Escherichia coli WP2 uvrA/pKM101
| 0 | 181 ± 46 | | | 136 ± 2 | 161 ± 7 | 266 ± 54 | 204 ± 12
| 100 | 90 ± 8 | | | 139 ± 4 | 141 ± 5 | 210 ± 2 | 224 ± 4
| 500 | 89 ± 2 | | | 175 ± 31 | 135 ± 12 | 208 ± 3 | 193 ± 13
| 1,000 | 84 ± 19 | | | 156 ± 9 | 137 ± 3 | 287 ± 46 | 207 ± 17
| 5,000 | 94 ± 5 | | | 148 ± 3 | 132 ± 4 | 162 ± 10 | 184 ± 21
| 10,000 | 78 ± 5 | | | 165 ± 10 | 126 ± 2 | 174 ± 24 | 188 ± 13
Trial summary | | Negative | | | Negative | Negative | Negative | Negative
Positive control | | 1,183 ± 140 | | | 930 ± 19 | 1,529 ± 121 | 710 ± 32 | 1,171 ± 10

^a^ Study was performed at SITEK Research Laboratories using a modification of the protocol presented by Zeiger et al.^56^ and the same lot of α-pinene (4KB705) used in the 3-month studies. Data are presented as revertants/plate (mean ± standard error) from three plates. 0 μg/plate was the solvent control.

^b^ The positive controls in the absence of metabolic activation were sodium azide (TA100), 4-nitro-o-phenylenediamine (TA98), and methyl methanesulfonate (E. coli). The positive control for metabolic activation with all strains was 2-aminoanthracene.

^c^ Slight toxicity.

^d^ Precipitate on plate.

Table B-2 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Mice Following Treatment with α-Pinene by Inhalation for Three Months^a^

| Concentration (ppm) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs^b^ (%)
Male
Air^d^ | | 5 | 1.6 ± 0.33 | | 2.50 ± 0.39
α-Pinene | 25 | 5 | 1.8 ± 0.30 | 0.3657 | 2.34 ± 0.19
| 50 | 5 | 1.9 ± 0.53 | 0.3059 | 2.20 ± 0.26
| 100 | 5 | 2.1 ± 0.43 | 0.2053 | 2.88 ± 0.31
| 200 | 5 | 1.9 ± 0.29 | 0.3059 | 2.74 ± 0.19
| 400 | 5 | 1.4 ± 0.40 | 0.6426 | 3.10 ± 0.20
| | | P = 0.742^e^
Female
Air | | 5 | 1.4 ± 0.19 | | 2.40 ± 0.19
α-Pinene | 25 | 5 | 2.1 ± 0.43 | 0.1182 | 2.16 ± 0.26
| 50 | 5 | 1.8 ± 0.25 | 0.2396 | 2.16 ± 0.20
| 100 | 5 | 1.7 ± 0.44 | 0.2949 | 2.74 ± 0.36
| 200 | 5 | 1.7 ± 0.30 | 0.2949 | 2.06 ± 0.29
| 400 | 5 | 1.1 ± 0.19 | 0.7259 | 2.16 ± 0.06
| | | P = 0.899

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by MacGregor et al.^57^ NCE = normochromatic erythrocyte; PCE = polychromatic erythrocyte.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the chamber control group, significant at P ≤ 0.005.

^d^ Chamber control.

^e^ Significance of micronucleated NCEs/1,000 NCEs tested by the one-tailed trend test; significant at P ≤ 0.025.