# Appendix A Summary of Neoplasms and Nonneoplastic Lesions in Rats and Mice

Table A-1 Summary of the Incidence of Nonneoplastic Lesions in Male Rats in the Three-month Inhalation Study of α-Pinene^a^

| Chamber Control | 25 ppm | 50 ppm | 100 ppm | 200 ppm | 400 ppm
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Survivors
Terminal kill | 10 | 10 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (10) | (10) | (10) | (10) | (10)
Clear cell focus | – | – | – | – | – | 1 (10%)
Hepatodiaphragmatic nodule | – | 1 (10%) | – | – | – | 1 (10%)
Mesentery | (0) | (1) | (0) | (0) | (0) | (0)
Fat, necrosis | – | 1 (100%) | – | – | – | –
Stomach, glandular | (10) | (0) | (0) | (0) | (0) | (10)
Mineralization | | – | – | – | – | 1 (10%)
Cardiovascular System
Heart | (10) | (0) | (0) | (0) | (0) | (10)
Cardiomyopathy | 6 (60%) | – | – | – | – | 8 (80%)
Endocrine System
None | – | – | – | – | – | –
General Body System
None | – | – | – | – | – | –
Genital System
Epididymis | (10) | (0) | (0) | (0) | (0) | (10)
Granuloma sperm | – | – | – | – | – | 1 (10%)
Hematopoietic System
Lymph node, mediastinal | (7) | (0) | (0) | (0) | (0) | (4)
Infiltration cellular, mast cell | – | – | – | – | – | 1 (25%)
Lymph node, mesenteric | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration cellular, mast cell | – | – | – | – | – | 1 (10%)
Integumentary System
None | – | – | – | – | – | –
Musculoskeletal System
None | – | – | – | – | – | –
Nervous System
Brain | (10) | (0) | (0) | (0) | (0) | (10)
Cerebellum, mineralization | 1 (10%) | – | – | – | – | –
Respiratory System
Lung | (10) | (0) | (0) | (0) | (0) | (10)
Hemorrhage | – | – | – | – | – | 1 (10%)
Inflammation, chronic active | 2 (20%) | – | – | – | – | 5 (50%)
Pleura | (0) | (0) | (0) | (0) | (0) | (1)
Inflammation, granulomatous | – | – | – | – | – | 1 (100%)
Special Senses System
Harderian gland | (10) | (0) | (0) | (0) | (0) | (10)
Inflammation, chronic | – | – | – | – | – | 1 (10%)
Urinary System
Kidney | (10) | (10) | (10) | (10) | (10) | (10)
Accumulation, hyaline droplet | 1 (10%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100)% | 10 (100%)
Casts granular | – | 9 (90%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%)
Nephropathy | 9 (90%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.

Table A-2 Summary of the Incidence of Nonneoplastic Lesions in Female Rats in the Three-month Inhalation Study of α-Pinene^a^

| Chamber Control | 25 ppm | 50 ppm | 100 ppm | 200 ppm | 400 ppm
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Early deaths
Natural deaths | – | – | – | – | – | 6
Survivors
Terminal kill | 10 | 10 | 10 | 10 | 10 | 4
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Mesentery | (1) | (1) | (3) | (0) | (0) | (0)
Fat, necrosis | 1 (100%) | 1 (100%) | 3 (100%) | – | – | –
Tongue | (0) | (1) | (0) | (0) | (0) | (0)
Cyst | – | 1 (100%) | – | – | – | –
Cardiovascular System
Heart | (10) | (0) | (0) | (0) | (10) | (10)
Cardiomyopathy | 3 (30%) | – | – | – | 2 (20%) | 1 (10%)
Endocrine System
None | – | – | – | – | – | –
General Body System
None | – | – | – | – | – | –
Genital System
Vagina | (0) | (1) | (0) | (0) | (0) | (0)
Cyst | – | 1 (100%) | – | – | – | –
Hematopoietic System
Lymph node, bronchial | (1) | (0) | (0) | (0) | (0) | (0)
Hemorrhage | 1 (100%) | – | – | – | – | –
Integumentary System
None | – | – | – | – | – | –
Musculoskeletal System
None | – | – | – | – | – | –
Nervous System
None | – | – | – | – | – | –
Respiratory System
Lung | (10) | (0) | (0) | (0) | (10) | (9)
Inflammation, chronic active | 4 (40%) | – | – | – | 2 (20%) | 5 (56%)
Alveolar epithelium, hyperplasia | – | – | – | – | 1 (10%) | –
Special Senses System
Eye | (10) | (0) | (0) | (0) | (9) | (10)
Cataract | – | – | – | – | 1 (11%) | –
Retina, atrophy | – | – | – | – | 1 (11%) | –
Urinary System
Kidney | (10) | (10) | (10) | (10) | (10) | (10)
Nephropathy | 1 (10%) | – | – | – | 1 (10%) | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.

Table A-3 Summary of the Incidence of Nonneoplastic Lesions in Male Mice in the Three-month Inhalation Study of α-Pinene^a^

| Chamber Control | 25 ppm | 50 ppm | 100 ppm | 200 ppm | 400 ppm
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Survivors
Terminal kill | 10 | 10 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Gallbladder | (9) | (0) | (0) | (0) | (0) | (7)
Infiltration cellular, polymorphonuclear | – | – | – | – | – | 1 (14%)
Pancreas | (10) | (0) | (0) | (1) | (0) | (10)
Duct, cyst | – | – | – | 1 (100%) | – | –
Cardiovascular System
None | – | – | – | – | – | –
Endocrine System
Adrenal cortex | (10) | (0) | (0) | (0) | (0) | (10)
Hypertrophy | 2 (20%) | – | – | – | – | –
General Body System
None | – | – | – | – | – | –
Genital System
None | – | – | – | – | – | –
Hematopoietic System
None | – | – | – | – | – | –
Integumentary System
None | – | – | – | – | – | –
Musculoskeletal System
None | – | – | – | – | – | –
Nervous System
None | – | – | – | – | – | –
Respiratory System
None | – | – | – | – | – | –
Special Senses System
None | – | – | – | – | – | –
Urinary System
Kidney | (10) | (10) | (10) | (10) | (10) | (10)
Dilatation | – | – | 1 (10%) | 1 (10%) | – | –
Nephropathy | – | – | 1 (10%) | 1 (10%) | – | 1 (10%)
Urinary bladder | (10) | (10) | (10) | (10) | (10) | (10)
Transitional epithelium, hyperplasia | – | – | – | 7 (70%) | 10 (100%) | 10 (100%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.

Table A-4 Summary of the Incidence of Neoplasms and Nonneoplastic Lesions in Female Mice in the Three-month Inhalation Study of α-Pinene^a^

| Chamber Control | 25 ppm | 50 ppm | 100 ppm | 200 ppm | 400 ppm
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Survivors
Terminal kill | 10 | 10 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Stomach, glandular | (10) | (0) | (0) | (0) | (0) | (10)
Mineralization | – | – | – | – | – | 1 (10%)
Cardiovascular System
None | – | – | – | – | – | –
Endocrine System
None | – | – | – | – | – | –
General Body System
None | – | – | – | – | – | –
Genital System
Ovary | (10) | (0) | (0) | (0) | (0) | (10)
Teratoma benign | 1 (10%) | – | – | – | – | –
Hematopoietic System
None | – | – | – | – | – | –
Integumentary System
None | – | – | – | – | – | –
Musculoskeletal System
None | – | – | – | – | – | –
Nervous System
None | – | – | – | – | – | –
Respiratory System
Lung | (10) | (0) | (0) | (0) | (0) | (10)
Alveolar epithelium, hyperplasia | – | – | – | – | – | 1 (10%)
Special Senses System
None | – | – | – | – | – | –
Urinary System
Kidney | (10) | (10) | (10) | (10) | (10) | (10)
Nephropathy | 2 (20%) | – | 1 (10%) | – | – | 1 (10%)
Urinary bladder | (10) | (10) | (10) | (10) | (10) | (10)
Transitional epithelium, hyperplasia | – | – | – | 6 (60%) | 10 (100%) | 10 (100%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.