# Peer Review

The draft NTP Technical Report on the Toxicity Studies of Sodium Thioglycolate (CASRN 367-51-1) Administered Dermally to F344/N Rats and B6C3F1/N Mice was evaluated by the reviewers listed below. These reviewers served as independent scientists, not as representatives of any institution, company, or governmental agency. In this capacity, reviewers determined if the design and conditions of these NTP studies were appropriate and ensured that this NTP Toxicity Study Report presented the experimental results and conclusions fully and clearly.

## Peer Reviewers

- Donna F. Kusewitt, D.V.M., Ph.D.
  Department of Molecular Carcinogenesis
  University of Texas MD Anderson Cancer Center
  Smithville, Texas, USA
- Robert H. Rice, Ph.D.
  Forensic Graduate Group
  University of California, Davis
  Davis, California, USA