# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  M. Mercado-Feliciano, Ph.D., Study Scientist
  M.J. Hooth, Ph.D., Co-Study Scientist
  J.B. Bishop, Ph.D.
  C.R. Blystone, M.S., Ph.D.
  R.S. Chhabra, Ph.D.
  P.M. Foster, Ph.D.
  A.P. King-Herbert, D.V.M.
  G.E. Kissling, Ph.D.
  D.E. Malarkey, D.V.M., Ph.D.
  B.S. McIntyre, Ph.D.
  C.S. Smith, Ph.D.
  G.S. Travlos, D.V.M.
  M.K. Vallant, M.T.
  S. Waidyantha, Ph.D.
  N.J. Walker, Ph.D.
  K.L. Witt, M.S.
- ILS, Inc., Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  A. Nyska, D.V.M., ILS, Inc., Study Pathologist
- BioReliance Corporation, Rockville, Maryland, USA
  Conducted studies and evaluated pathology findings
  M.L. Wenk, Ph.D., Principal Investigator
  L.L. Lanning, D.V.M.
  D.R. Ragland, D.V.M., M.M.S.
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Conducted pathology review
  K.J. Cimon, D.V.M., M.S.
- Pathology Associates, A Division of Charles River Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Coordinated NTP Pathology Working Group (July 1, 2004)
  J.C. Turnier, V.M.D.
- TherImmune Research Corporation, Gaithersburg, Maryland, USA
  Provided SMVCE analysis
  H. Seung, M.S.
  G.W. Wolfe, Ph.D.