# References

1 Hawley’s condensed chemical dictionary. 13th ed. Lewis Reditor. New York (NY): Van Nostrand Reinhold; 1997.
2 CTFA cosmetic ingredient handbook. Nikitakis Jeditor. Washington (DC): The Cosmetic, Toiletry, and Fragrance Association, Inc; 1988.
3 The Merck Index. In: Budavari Seditor. The Merck Index. New Jersey, NJ. Whitehouse Station; 1996 b. p. 1484.
4 The Merck Index. In: Budavari Seditor. The Merck Index. New Jersey, NJ. Whitehouse Station; 1996 a. p. 1593.
5 United States Environmental Protection Agency (USEPA). Inventory Update Reporting (IUR): Non-confidential 2006 IUR company/chemical records. 2012. https://www.epa.gov/oppt/iur/tools/data/index.html [Accessed: August 23, 2012]
6 Burnett CL Bergfeld WF Belsito DV Klaassen CD Marks JG Jr Shank RC Slaga TJ Snyder PW Andersen FA Cosmetic Ingredient Review Expert Panel Final amended report on the safety assessment of ammonium thioglycolate, butyl thioglycolate, calcium thioglycolate, ethanolamine thioglycolate, ethyl thioglycolate, glyceryl thioglycolate, isooctyl thioglycolate, isopropyl thioglycolate, magnesium thioglycolate, methyl thioglycolate, potassium thioglycolate, sodium thioglycolate, and thioglycolic acid. Int J Toxicol. 2009;28(4) Suppl:68–133. 10.1177/1091581809339890 19636068
7 Hazardous Substances Data Bank (HSDB). National Institutes for Occupational Safety and Health (NIOSH); 2002. https://toxnet.nlm.nih.gov/cgi-bin/sis/htmlgen?HSDB.
8 National Institute of Occupational Safety and Health (NIOSH). National Occupational Exposure Survey (1981-1983), unpublished provisional data as of July 1, 1990. Cincinnati, OH: NIOSH. 1990.
9 American Conference of Governmental Industrial Hygienists (ACGIH). 2011 TLVs® and BEIs® based on the documentation of the threshold limit values for chemical substances and physical agents & biological exposure indices. Cincinnati, OH; 2011.
10 National Institute for Occupational Safety and Health (NIOSH). NIOSH recommendations for occupational safety and health. Cincinnati, OH: U.S. Department of Health and Human Services, Public Health Service, Centers for Disease Control, National Institute for Occupational Safety and Health; 1992. DHHS Publication No. 92-100.
11 Draize JH Freeman MV Smith PK Some aspects of the absorption, distribution and excretion of sodium thioglycolate. J Pharmacol Exp Ther. 1956;118(3):304–308. 13377298
12 Bakshy S Gershbein LL Metabolism of S 35 -labeled thioglycolate. Arch Int Pharmacodyn Ther. 1972;197(1):5–13. 5031580
13 Gershbein LL Percutaneous toxicity of thioglycolate mixtures in rabbits. J Pharm Sci. 1979;68(10):1230–1235. 10.1002/jps.2600681009 512851
14 Draize JH Freeman MV Smith PK Some aspects of the mechanism of toxicity of thioglycolate. J Pharmacol Exp Ther. 1956;118(3):296–303. 13377297
15 Cosmetic Ingredient Review (CIR). Final report on the safety assessment of ammonium and glyceryl thioglycolates and thioglycolic acid. J Am Coll Toxicol. 1991;10:135–192. 10.3109/10915819109078628
16 Registry of Toxic Effects of Chemical Substances (RTECS). Acetic acid, mercapto-, monosodium salt. 2003. https://www.cdc.gov/niosh/rtecs/ai757e20.html [Accessed: April 21, 2005]
17 Del Prete E Lutz TA Althaus J Scharrer E Inhibitors of fatty acid oxidation (mercaptoacetate, R-3-amino-4-trimethylaminobutyric acid) stimulate feeding in mice. Physiol Behav. 1998;63(5):751–754. 10.1016/S0031-9384(97)00527-1 9617995
18 Garosi VL Nisoli E Blundell JE Carruba MO Pharmacological antagonism of lipoprivic feeding induced by sodium mercaptoacetate. Eur J Pharmacol. 1995;276(3):285–289. 10.1016/0014-2999(95)00087-2 7601216
19 Singer-Koegler LK Magluyan P Ritter S The effects of low-, medium-, and high-fat diets on 2-deoxy-D-glucose- and mercaptoacetate-induced feeding. Physiol Behav. 1996;60(1):321–323. 10.1016/0031-9384(95)02142-6 8804684
20 Scharrer E Langhans W Control of food intake by fatty acid oxidation. Am J Physiol. 1986;250(6):R1003–R1006. 10.1152/ajpregu.1986.250.6.R1003 3717372
21 European Chemicals Agency (ECHA). 2012. http://apps.echa.europa.eu/registered/data/dossiers/DISS-9ebe899b-ae90-534d-e044-00144f67d031/AGGR-f4aaeb65-13fa-41c5-aed2-10df122546aa_DISS-9ebe899b-ae90-534d-e044-00144f67d031.html#AGGR-f4aaeb65-13fa-41c5-aed2-10df122546aa [Accessed: December 5, 2012]
22 Tyl RW Price CJ Marr MC Myers CB van Birgelen AP Jahnke GD Developmental toxicity evaluation of sodium thioglycolate administered topically to Sprague-Dawley (CD) rats and New Zealand White rabbits. Birth Defects Res B Dev Reprod Toxicol. 2003;68(2):144–161. 10.1002/bdrb.10001 12866706
23 Walker J. A personal communication (facsimile transmittal) from John Walker, Ph.D., M.P.H., Executive Director, TSCA Interagency Testing Committee, Environmental Protection Agency, Washington, DC, to Victor Fung, Ph.D., National Cancer Institute, Division of Cancer Biology, 6/8/95 (cited in Tyl et al. 2003). 1995.
24 Walker J. A personal communication (facsimile transmittal) from John Walker, Ph.D., M.P.H., Executive Director, TSCA Interagency Testing Committee, Environmental Protection Agency, Washington, DC, to Victor Fung, Ph.D., National Cancer Institute, Division of Cancer Biology, 4/26/95 (cited in Tyl et al. 2003). 1995.
25 Stenbäck FG Rowland JC Russell LA Non-carcinogenicity of hair dyes: lifetime percutaneous applications in mice and rabbits. Food Cosmet Toxicol. 1977;15(6):601–606. 10.1016/0015-6264(77)90076-1 604237
26 Gocke E King M-T Eckhardt K Wild D Mutagenicity of cosmetics ingredients licensed by the European Communities. Mutat Res. 1981;90(2):91–109. 10.1016/0165-1218(81)90072-0 6799819
27 Zeiger E Anderson B Haworth S Lawlor T Mortelmans K Speck W Salmonella mutagenicity tests: III. Results from the testing of 255 chemicals. Environ Mutagen. 1987;9 Suppl 9:1–109. 10.1002/em.2860090602 3552650
28 Maronpot RR Boorman GA Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982;10(2):71–78. 10.1177/019262338201000210 28094716
29 Boorman GA Montgomery CA Jr Eustis SL Wolfe MJ McConnell EE Hardisty JF Quality assurance in pathology for rodent carcinogenicity studies. In: Milman HA Weisburger EKeditors. Handbook of Carcinogen Testing. Park Ridge (NJ): Noyes Publications; 1985. p. 345–357.
30 Gart JJ Chu KC Tarone RE Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979;62(4):957–974. 285297
31 Dunnett CW A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955;50(272):1096–1121. 10.1080/01621459.1955.10501294
32 Williams DA The comparison of several dose levels with a zero dose control. Biometrics. 1972;28(2):519–531. 10.2307/2556164 5037867
33 Williams DA A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971;27(1):103–117. 10.2307/2528930 5547548
34 Shirley E A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977;33(2):386–389. 10.2307/2529789 884197
35 Williams DA A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986;42(1):183–186. 10.2307/2531254 3719054
36 Dunn OJ Multiple comparisons using rank sums. Technometrics. 1964;6(3):241–252. 10.1080/00401706.1964.10490181
37 Jonckheere A A distribution-free k-sample test against ordered alternatives. Biometrika. 1954;41:133–145. 10.1093/biomet/41.1-2.133
38 Dixon W Massey F Introduction to statistical analysis. New York (NY): McGraw Hill Book Company Inc; 1957. 10.2307/2332898
39 Girard DM Sager DB The use of Markov chains to detect subtle variation in reproductive cycling. Biometrics. 1987;43(1):225–234. 10.2307/2531963 3567307
40 Code of Federal Regulations (CFR). 21:Part 58.
41 MacGregor JT Wehr CM Henika PR Shelby MD The in vivo erythrocyte micronucleus test: measurement at steady state increases assay efficiency and permits integration with toxicity studies. Fundam Appl Toxicol. 1990;14(3):513–522. 10.1016/0272-0590(90)90255-I 2111256
42 Witt KL, Knapton A, Wehr CM, Hook GJ, Mirsalis J, Shelby MD, MacGregor JT. Micronucleated erythrocyte frequency in peripheral blood of B6C3F1 mice from short‐term, prechronic, and chronic studies of the NTP carcinogenesis bioassay program. Environ Mol Mutagen. 2000; 36(3):163-194. 10.1002/1098-2280(2000)36:3<163::AID-EM1>3.0.CO;2-P
43 Sadtler Standard Spectra IR Spectrum No. 7036. Philadelphia (PA): Sadtler Research Laboratories; 1970.