# Results

## Rats

### Two-week Study

All rats survived to the end of the study (Table 2). Mean body weights of dosed groups were similar to those of the vehicle control groups. On day 17, all 180 mg/kg males, two 90 mg/kg females, and two 180 mg/kg females had irritation at the site of application.

Table 2 Survival and Body Weights of Rats in the Two-week Dermal Study of Sodium Thioglycolate^a^

Dose (mg/kg) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 5/5 | 86 ± 6 | 151 ± 11 | 65 ± 4
11.25 | 5/5 | 93 ± 2 | 148 ± 4 | 56 ± 3 | 98
22.5 | 5/5 | 93 ± 2 | 162 ± 4 | 69 ± 3 | 107
45 | 5/5 | 87 ± 4 | 152 ± 5 | 65 ± 3 | 101
90 | 5/5 | 92 ± 1 | 164 ± 4 | 72 ± 4 | 109
180 | 5/5 | 91 ± 2 | 162 ± 6 | 71 ± 4 | 107
Female
0 | 5/5 | 89 ± 2 | 128 ± 3 | 38 ± 2
11.25 | 5/5 | 81 ± 5 | 117 ± 6 | 37 ± 3 | 92
22.5 | 5/5 | 88 ± 1 | 115 ± 3 | 27 ± 3 | 90
45 | 5/5 | 86 ± 5 | 118 ± 5 | 32 ± 5 | 93
90 | 5/5 | 92 ± 2 | 120 ± 2 | 27 ± 3 | 94
180 | 5/5 | 89 ± 2 | 125 ± 2 | 36 ± 2 | 98

^a^ Weights and weight changes are given as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test.

^b^ Number of animals surviving at day 17/number initially in group.

Absolute kidney weights were significantly increased in 90 and 180 mg/kg males; relative kidney weights were significantly increased in 180 mg/kg males (Table 3 and Table D-1). Absolute and relative liver weights were significantly increased in 180 mg/kg males. Absolute and relative lung weights were significantly decreased in all groups of dosed males. Minimal epidermal hyperplasia occurred in male and female rats administered 45 mg/kg or greater (male: 0/5, 0/5, 0/5, 4/5, 2/5, 4/5; female: 0/5, 0/5, 0/5, 2/5, 2/5, 4/5). Mild cytoplasmic focal vacuolization of the centrilobular hepatocytes occurred in all groups of dosed males (0/5, 2/5, 3/5, 3/5, 3/5, 4/5). There were no histopathologic findings associated with the changes in kidney or lung weights in male rats. Other than epidermal hyperplasia, no effects were observed in female rats.

Table 3 Selected Organ Weights and Organ-Weight-to-Body-Weight Ratios for Male Rats in the Two-week Dermal Study of Sodium Thioglycolate^a^

| Vehicle Control | 11.25 mg/kg | 22.5 mg/kg | 45 mg/kg | 90 mg/kg | 180 mg/kg
n | 5 | 5 | 5 | 5 | 5 | 5
Necropsy body wt | 151 ± 11 | 148 ± 4 | 162 ± 4 | 152 ± 5 | 164 ± 4 | 162 ± 6
R. Kidney
Absolute | 0.719 ± 0.037 | 0.738 ± 0.025 | 0.811 ± 0.028 | 0.754 ± .037 | 0.823 ± 0.026* | 0.861 ± 0.033**
Relative | 4.790 ± 0.107 | 4.977 ± 0.072 | 4.994 ± 0.077 | 4.952 ± 0.111 | 5.003 ± 0.109 | 5.325 ± 0.118**
Liver
Absolute | 7.921 ± 0.632 | 8.080 ± 0.301 | 8.715 ± 0.299 | 7.817 ± .309 | 9.082 ± 0.363 | 9.525 ± 0.375*
Relative | 52.348 ± 1.267 | 54.567 ± 1.960 | 53.696 ± 1.035 | 51.460 ± 1.353 | 55.256 ± 1.972 | 58.881 ± 0.842*
Lung
Absolute | 1.801 ± 0.067 | 0.996 ± 0.031** | 1.054 ± 0.052** | 0.954 ± 0.056** | 0.991 ± 0.060** | 0.990 ± 0.061**
Relative | 12.220 ± 1.155 | 6.728 ± 0.205** | 6.511 ± 0.361** | 6.274 ± 0.285** | 6.011 ± 0.257** | 6.129 ± 0.347**

* Significantly different (P ≤ 0.05) from the vehicle control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Dose Selection Rationale: Due to the lack of systemic toxicity and minimal dermal toxicity at the site of application, the sodium thioglycolate doses selected for the 3-month rat study were the same as those used in the 2-week study.

### Three-month Study

All rats survived to the end of the study; final mean body weights and body weight gains of 90 and 180 mg/kg males were significantly less than those of the vehicle controls, but were within 10% of vehicle control values (Table 4 and Figure 2). Feed consumption by dosed groups of male and female rats was generally similar to that by the vehicle control groups (Table G-1 and Table G-2). All dosed rats developed irritation at the site of application. Thickening of the skin at the site of application in 90 and 180 mg/kg males and in females administered 45 mg/kg or greater and ulceration of the skin at the site of application in 90 and 180 mg/kg males and females were observed.

Table 4 Survival and Body Weights of Rats in the Three-month Dermal Study of Sodium Thioglycolate^a^

Dose (mg/kg) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 93 ± 2 | 335 ± 4 | 242 ± 4
11.25 | 10/10 | 92 ± 2 | 334 ± 4 | 242 ± 4 | 100
22.5 | 10/10 | 91 ± 3 | 332 ± 7 | 241 ± 6 | 99
45 | 10/10 | 94 ± 3 | 339 ± 5 | 246 ± 3 | 101
90 | 10/10 | 90 ± 3 | 312 ± 9* | 222 ± 7* | 93
180 | 10/10 | 92 ± 3 | 319 ± 6* | 227 ± 5* | 95
Female
0 | 10/10 | 85 ± 2 | 177 ± 3 | 92 ± 2
11.25 | 10/10 | 84 ± 2 | 185 ± 3 | 101 ± 2* | 105
22.5 | 10/10 | 85 ± 2 | 185 ± 3 | 100 ± 2 | 106
45 | 10/10 | 86 ± 2 | 186 ± 3 | 100 ± 2 | 105
90 | 10/10 | 83 ± 2 | 180 ± 4 | 97 ± 3 | 101
180 | 10/10 | 82 ± 3 | 173 ± 4 | 91 ± 2 | 98

* Significantly different (P ≤ 0.05) from the vehicle control group by Williams’ or Dunnett’s test.

^a^ Weights and weight changes are given as mean ± standard error.

^b^ Number of animals surviving at 3 months/number initially in group.

Figure 2

Growth Curves for Rats Administered Sodium Thioglycolate Dermally for Three Months

No chemical-related changes in hematology or clinical chemistry variables occurred (Table C-1). Organ weight changes were considered sporadic or related to a decrease in body weight so were not considered to be biologically significant (Table D-2). There were no significant differences in sperm parameters of male rats or estrous cyclicity of female rats administered 45, 90, or 180 mg/kg sodium thioglycolate when compared to the vehicle controls (Table E-1 and Table E-2).

Chemical-related nonneoplastic lesions were limited to the site of application (Table 5, Table A-1, and Table A-2). These lesions included epidermal hyperplasia (thickening), hyperkeratosis (thickening of the stratum corneum), sebaceous gland hypertrophy (increase in the size of the cells), and ulcers (discontinuity in the epithelial surface that extended through the full thickness of the epithelial surface) (Figure 4 and Figure 5). Lesions were minimal to mild, involving all treatment groups. Ulceration was noted only in three females treated with 180 mg/kg. The following severity criteria were applied to grade the epidermal hyperplasia: minimal hyperplasia was two to three cell layers thick; mild was four to six cell layers thick; moderate was seven to eight cell layers thick; and marked was equal to or greater than nine cell layers thick.

Table 5 Incidences of Nonneoplastic Lesions of the Skin at the Site of Application in Rats in the Three-month Dermal Study of Sodium Thioglycolate

| Vehicle Control | 11.25 mg/kg | 22.5 mg/kg | 45 mg/kg | 90 mg/kg | 180 mg/kg
Male
Number Examined Microscopically | 10 | 10 | 10 | 10 | 10 | 10
Sebaceous Gland, Dermis, Hypertrophy^a^ | 0 | 0 | 2 (1.0)^b^ | 4* (1.0) | 5* (1.0) | 6** (1.0)
Epidermis, Hyperkeratosis | 0 | 6** (1.0) | 9** (1.0) | 4* (1.0) | 4* (1.0) | 4* (1.0)
Epidermis, Hyperplasia, Diffuse | 0 | 1 (1.0) | 2 (1.0) | 3 (1.0) | 5* (1.0) | 6** (1.0)
Female
Number Examined Microscopically | 10 | 10 | 10 | 10 | 10 | 10
Sebaceous Gland, Dermis, Hypertrophy | 0 | 0 | 0 | 2 (1.0) | 6** (1.0) | 5* (1.0)
Epidermis, Hyperkeratosis | 0 | 0 | 1 (1.0) | 7** (1.0) | 6** (1.0) | 5* (1.0)
Epidermis, Hyperplasia, Diffuse | 0 | 0 | 0 | 2 (1.0) | 7** (1.3) | 8** (1.5)
Epidermis, Ulcer, Focal | 0 | 0 | 0 | 0 | 0 | 3 (1.0)

* Significantly different (P ≤ 0.05) from the vehicle control group by the Fisher exact test.

** P ≤ 0.01.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Figure 4

Normal Aspect of the Skin from a Vehicle Control Male Rat in the Three-month Dermal Study of Sodium Thioglycolate (H&E)

Figure 5

Diffuse, Minimal Epidermal Hyperplasia (Thickening) of the Skin of a Male Rat Dermally Administered 180 mg Sodium Thioglycolate/kg Body Weight per Day for Three Months (H&E)

## Mice

### Two-week Study

All male mice survived to the end of the study; one 360 mg/kg female was found dead on day 5 with cause of death unknown: no clinical findings, gross lesions, or significant histologic lesions were observed (Table 6). The mean body weight gain of 180 mg/kg males was significantly greater than that of the vehicle control group. No clinical findings attributed to sodium thioglycolate administration were observed. No biologically significant organ weight differences were observed (Table D-3).

Table 6 Survival and Body Weights of Mice in the Two-week Dermal Study of Sodium Thioglycolate^a^

Dose (mg/kg) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 5/5 | 21.4 ± 0.6 | 23.6 ± 0.5 | 2.2 ± 0.4
22.5 | 5/5 | 20.8 ± 0.5 | 23.5 ± 0.3 | 2.7± 0.3 | 99
45 | 5/5 | 21.5 ± 0.7 | 24.7 ± 0.9 | 3.2 ± 0.4 | 105
90 | 5/5 | 21.5 ± 0.3 | 23.9 ± 0.3 | 2.4 ± 0.3 | 101
180 | 5/5 | 21.3 ± 0.4 | 25.1 ± 0.4 | 3.8 ± 0.2** | 106
360 | 5/5 | 21.5 ± 0.4 | 24.7 ± 0.4 | 3.2 ± 0.2 | 105
Female
0 | 5/5 | 18.2 ± 0.2 | 21.3 ± 0.2 | 3.1 ± 0.2
22.5 | 5/5 | 18.3 ± 0.3 | 21.2 ± 0.3 | 2.9 ± 0.4 | 100
45 | 5/5 | 18.9 ± 0.4 | 21.5 ± 0.2 | 2.6 ± 0.3 | 101
90 | 5/5 | 18.4 ± 0.6 | 21.8 ± 0.3 | 3.3 ± 0.7 | 102
180 | 5/5 | 18.3 ± 0.5 | 22.1 ± 0.5 | 3.9 ± 0.5 | 104
360 | 4/5^c^ | 18.3 ± 0.6 | 22.2 ± 0.6 | 3.9 ± 0.4 | 104

** Significantly different (P ≤ 0.01) from the vehicle control group by Dunnett’s test.

^a^ Weights and weight changes are given as mean ± standard error. Subsequent calculations are based on animals surviving to the end of the study.

^b^ Number of animals surviving at day 18/number initially in group.

^c^ Day of death: 5.

No chemical-related gross lesions were observed. Minimal to mild epidermal hyperplasia occurred in male mice administered 90 mg/kg or greater and in female mice administered 45 mg/kg or greater (male: 0/5, 0/5, 0/5, 3/5, 5/5, 5/5; female: 0/5, 0/5, 1/5, 3/5, 4/5, 3/5).

Dose Selection Rationale: Due to the lack of systemic toxicity and minimal dermal toxicity at the site of application, the sodium thioglycolate doses selected for the 3-month mouse study were the same as those used in the 2-week study.

### Three-month Study

All mice survived to the end of the study; mean body weights of dosed groups were similar to those of the vehicle control groups (Table 7; Figure 3). Feed consumption by dosed groups of male and female mice was generally similar to that of the vehicle control groups (Table G-3 and Table G-4). Six 360 mg/kg males developed irritation at the site of application.

Table 7 Survival and Body Weights of Mice in the Three-month Dermal Study of Sodium Thioglycolate^a^

Dose (mg/kg) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 21.0 ± 0.2 | 29.0 ± 0.5 | 8.0 ± 0.4
22.5 | 10/10 | 20.5 ± 0.2 | 28.2 ± 0.3 | 7.7 ± 0.3 | 97
45 | 10/10 | 21.0 ± 0.2 | 28.1 ± 0.7 | 7.1 ± 0.7 | 97
90 | 10/10 | 21.0 ± 0.3 | 28.2 ± 0.6 | 7.3 ± 0.5 | 97
180 | 10/10 | 20.6 ± 0.3 | 28.8 ± 0.4 | 8.2 ± 0.3 | 99
360 | 10/10 | 20.8 ± 0.2 | 28.3 ± 0.3 | 7.5 ± 0.2 | 98
Female
0 | 10/10 | 17.6 ± 0.3 | 24.4 ± 0.5 | 6.8 ± 0.3
22.5 | 10/10 | 17.4 ± 0.3 | 24.8 ± 0.4 | 7.4 ± 0.3 | 102
45 | 10/10 | 17.5 ± 0.3 | 25.4 ± 0.7 | 8.0 ± 0.7 | 104
90 | 10/10 | 17.7 ± 0.3 | 24.6 ± 0.5 | 6.9 ± 0.3 | 101
180 | 10/10 | 17.7 ± 0.3 | 25.3 ± 0.4 | 7.6 ± 0.3 | 104
360 | 10/10 | 17.7 ± 0.2 | 25.5 ± 0.4 | 7.9 ± 0.4 | 105

^a^ Weights and weight changes are given as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test.

^b^ Number of animals surviving at 3 months/number initially in group.

Figure 3

Growth Curves for Mice Administered Sodium Thioglycolate Dermally for Three Months

The hematology data for mice are listed in Table C-2. Minimal (<8%) treatment- but not dose-related decreases in hematocrit values, hemoglobin concentrations, and/or erythrocyte counts, occurred in dosed female mice. These findings could suggest a minimal erythron effect in the females. However, the lack of a dose relationship and the minimal nature of the decreases make the toxicological significance of these findings questionable. There were no significant differences in sperm parameters of male mice or estrous cyclicity of female mice administered 90, 180, or 360 mg/kg when compared to the vehicle controls (Table E-3 and Table E-4). Female mice did exhibit a weak dose-related decrease in the proportion of females with regular cycles (vehicle controls, 9/10; 90 mg/kg, 10/10; 180 mg/kg, 8/10; 360 mg/kg, 6/10); however, none of the dose groups were significantly different from the control group. This is not considered sufficient to indicate potential for reproductive toxicity.

Absolute heart weights were significantly increased in 180 and 360 mg/kg males and 45 mg/kg or greater females; relative heart weights were significantly increased in 22.5 mg/kg or greater males and 360 mg/kg females (Table 8 and Table D-4). Absolute liver weights were significantly increased in 180 and 360 mg/kg males and 22.5 mg/kg or greater females; relative liver weights were significantly increased in 90 mg/kg or greater males and 45 mg/kg or greater females. Absolute kidney weights were significantly increased in 180 and 360 mg/kg females. No histologic findings correlating with the significant organ weights changes were seen in the liver, heart, or kidneys.

Table 8 Selected Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Three-month Dermal Study of Sodium Thioglycolate

| Vehicle Control | 22.5 mg/kg | 45 mg/kg | 90 mg/kg | 180 mg/kg | 360 mg/kg
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 29.0 ± 0.5 | 28.2 ± 0.3 | 28.1 ± 0.7 | 28.2 ± 0.6 | 28.8 ± 0.4 | 28.3 ± 0.3
Heart
Absolute | 0.137 ± 0.002 | 0.147 ± 0.002 | 0.147 ± 0.004 | 0.141 ± 0.002 | 0.148 ± 0.002* | 0.148 ± 0.002*
Relative | 4.725 ± 0.041 | 5.196 ± 0.087** | 5.213 ± 0.087** | 5.018 ± 0.110** | 5.141 ± 0.067** | 5.247 ± 0.080**
Liver
Absolute | 1.300 ± 0.022 | 1.281 ± 0.028 | 1.251 ± 0.023 | 1.329 ± 0.035 | 1.404 ± 0.025** | 1.409 ± 0.025**
Relative | 44.876 ± 0.512 | 45.361 ± 0.801 | 44.580 ± 0.621 | 47.151 ± 0.851* | 48.771 ± 0.692** | 49.844 ± 0.696**
Female
Necropsy body wt | 24.4 ± 0.5 | 24.8 ± 0.4 | 25.4 ± 0.7 | 24.6 ± 0.5 | 25.3 ± 0.4 | 25.5 ± 0.4
Heart
Absolute | 0.124 ± 0.003 | 0.131 ± 0.003 | 0.134 ± 0.002* | 0.129 ± 0.002* | 0.134 ± 0.003** | 0.140 ± 0.003**
Relative | 5.074 ± 0.097 | 5.278 ± 0.094 | 5.300 ± 0.117 | 5.257 ± 0.104 | 5.307 ± 0.135 | 5.481 ± 0.109*
R. Kidney
Absolute | 0.179 ± 0.006 | 0.189 ± 0.005 | 0.191 ± 0.004 | 0.184 ± 0.004 | 0.196 ± 0.003* | 0.198 ± 0.002*
Relative | 7.350 ± 0.166 | 7.610 ± 0.180 | 7.531 ± 0.201 | 7.482 ± 0.133 | 7.743 ± 0.089 | 7.755 ± 0.111
Liver
Absolute | 1.118 ± 0.030 | 1.197 ± 0.029* | 1.256 ± 0.025** | 1.233 ± 0.033** | 1.285 ± 0.019** | 1.337 ± 0.027**
Relative | 45.867 ± 0.844 | 48.279 ± 0.873 | 49.544 ± 1.129** | 50.063 ± 0.924** | 50.930 ± 0.677** | 52.404 ±0.821**

* Significantly different (P ≤ 0.05) from the vehicle control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

No chemical-related gross lesions were observed at necropsy. Microscopically, nonneoplastic lesions were limited to the site of application (Table 9, Table A-3, and Table A-4). These observations included focal or diffuse epidermal hyperplasia (thickening), hyperkeratosis (thickening of the stratum corneum), and sebaceous gland hypertrophy (increase in the size of the cells) (Figure 6 and Figure 7). Most observations were minimal to mild and often difficult to distinguish from normal. The dose relation of the lesions was apparent only in the 180 and 360 mg/kg groups. The following severity criteria were applied to grade the epidermal hyperplasia: minimal hyperplasia was two to three cell layers thick; mild was four to six cell layers thick; moderate was seven to eight cell layers thick; and marked was equal to or greater than nine cell layers thick.

Table 9 Incidences of Nonneoplastic Lesions of the Skin at the Site of Application in Mice in the Three-month Dermal Study of Sodium Thioglycolate

| Vehicle Control | 22.5 mg/kg | 45 mg/kg | 90 mg/kg | 180 mg/kg | 360 mg/kg
Male
Number Examined Microscopically | 10 | 10 | 10 | 10 | 10 | 10
Sebaceous Gland, Dermis, Hypertrophy^a^ | 0 | 0 | 0 | 0 | 2 (1.0)^b^ | 4* (1.0)
Epidermis, Hyperkeratosis | 0 | 0 | 0 | 0 | 3 (1.0) | 3 (1.0)
Epidermis, Hyperplasia, Diffuse | 0 | 0 | 0 | 0 | 3 (1.0) | 6** (2.2)
Female
Number Examined Microscopically | 10 | 10 | 10 | 10 | 10 | 10
Sebaceous Gland, Dermis, Hypertrophy | 0 | 0 | 0 | 0 | 6** (1.0) | 7** (1.0)
Epidermis, Hyperkeratosis | 0 | 0 | 0 | 1 (1.0) | 1 (1.0) | 4* (1.3)
Epidermis, Hyperplasia, Diffuse | 0 | 0 | 0 | 0 | 6** (1.5) | 8** (1.5)
Epidermis, Hyperplasia, Focal | 0 | 1 (3.0) | 3 (1.0) | 1 (1.0) | 3 (1.0) | 2 (1.0)

* Significantly different (P ≤ 0.05) from the vehicle control group by the Fisher exact test.

** P ≤ 0.01.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Figure 6

Normal Aspect of the Skin from a Vehicle Control Male Mouse in the Three-month Dermal Study of Sodium Thioglycolate (H&E)

Figure 7

Diffuse, Mild Epidermal Hyperplasia (Thickening) of the Skin of a Male Mouse Dermally Administered 180 mg Sodium Thioglycolate/kg Body Weight per Day for Three Months (H&E)

## Genetic Toxicology

Sodium thioglycolate (10 to 1,000 µg/plate) was not mutagenic in Salmonella typhimurium strains TA98, TA100, TA1535, or TA1537 when tested with or without rat or hamster liver S9 activation enzymes (Table B-1; Zeiger et al.27). Dermal exposure to sodium thioglycolate for 3 months resulted in a small but significant (P = 0.002) increase in the frequency of micronucleated normochromatic erythrocytes in peripheral blood of female mice but not male mice (Table B-2). All dosed groups of male and female mice showed higher frequencies of micronucleated normochromatic erythrocytes compared to the vehicle control groups, but only the mean value seen in female mice treated with the highest dose of sodium thioglycolate was significantly increased. No significant dose-related alterations in the percentage of polychromatic erythrocytes (immature erythrocytes) were noted in either male or female mice treated with sodium thioglycolate, indicating an absence of bone marrow toxicity.