# Materials and Methods

## Procurement and Characterization

### Sodium Thioglycolate

Sodium thioglycolate was obtained by the analytical chemistry laboratory (Midwest Research Institute, Kansas City, MO) from Sigma Chemical Company (Columbus, OH) in one lot (88H1166) that was used in the 2-week and 3-month studies. Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory (Appendix F). Reports on analyses performed in support of the sodium thioglycolate studies are on file at the National Institute of Environmental Health Sciences.

The chemical, a white powder, was identified as sodium thioglycolate by infrared and proton and carbon-13 nuclear magnetic resonance spectroscopy. The purity of lot 88H1166 was determined by ion chromatography. Purity assays indicated one major peak and three impurities with a combined area of approximately 1% relative to the total peak area. The overall purity of lot 88H1166 was determined to be approximately 99%.

Stability studies of a different lot of the bulk chemical were performed by the analytical chemistry laboratory using ion chromatography. These studies indicated that sodium thioglycolate was stable as a bulk chemical for 14 days when stored protected from light frozen (−20°C), refrigerated (5°C), and heated (60°C) but not at ambient (25°C) temperature. To ensure stability, the bulk chemical was stored under a headspace of inert gas at less than or equal to −20°C, protected from light, in amber glass bottles. The analytical chemistry laboratory reanalyzed the bulk chemical at the end of the 3-month study by ion chromatography. No degradation of the bulk chemical was detected.

### 95% Ethanol

95% Ethanol, a clear liquid, was obtained from Pharmco Products, Inc. (Brookfield, CT), in two lots (P1107 and R8092); lot P1107 was used in the 2-week studies, and lot R8092 was used in the 3-month studies. The study laboratory (BioReliance Corporation, Rockville, MD) identified lot R8092 of the chemical as ethanol by infrared spectroscopy and determined the purities of both lots of the chemical using gas chromatography; no impurity peaks were noted.

## Preparation and Analysis of Dose Formulations

The dose formulations were prepared on three separate days during the 2-week studies and approximately weekly during the 3-month studies by mixing sodium thioglycolate and the vehicle [95% ethanol:deionized water (1:1)] to give the required concentration. The dose formulations were stored under an inert gas headspace at 2° to 8°C in amber vials sealed with Teflon^®^-lined septa and aluminum seals for up to 10 days. Fresh dosing bottles were used each day.

Stability studies of a 3.1 mg/mL dose formulation of a different lot were performed by the analytical chemistry laboratory using ion chromatography. Stability was confirmed for at least 10 days for dose formulations stored at approximately 5°C in sealed amber vials and for at least 3 hours for dose formulations exposed to ambient temperature and light.

Periodic analyses of samples of the dose formulations of sodium thioglycolate were conducted by the analytical chemistry laboratory because ion chromatography was not available at the study laboratory. Samples of formulations were collected in amber glass vials under inert gas headspace and shipped on dry ice for overnight delivery to the analytical chemistry laboratory. Animal room samples were collected similarly following dosing on the last day of the use period. During the 2-week studies, the dose formulations were analyzed twice; nine of 10 dose formulations for rats and eight of 10 dose formulations for mice were within 10% of the target concentrations. For animal room samples analyzed, three of five for rats and three of five for mice were within 10% of the target concentrations. During the 3-month studies, the dose formulations were analyzed at the beginning, midpoint, and end of the studies; animal room samples of these dose formulations were also analyzed. Of the dose formulations analyzed, all 15 for rats and all 15 for mice were within 10% of the target concentrations; two of 15 animal room samples analyzed for rats and four of 15 animal room samples analyzed for mice were within 10% of the target concentrations.

## Two-week Studies

Two-week studies were conducted to evaluate the cumulative toxic effects of repeated applications of sodium thioglycolate and to determine the appropriate doses to be used in the 3-month studies. The highest dose concentration for the 2-week rat study was limited by the maximum solubility of sodium thioglycolate in the test vehicle. The maximum concentration determined for the test article solubility was 364 mg sodium thioglycolate per mL of 95% ethanol:deionized water. Therefore, the highest dose selected for rats was 180 mg/kg (0.5 mL/kg dosing volume). For the 2-week mouse study, the highest dose possible based on the solubility of sodium thioglycolate would have exceeded the LD_50_ values in the literature (2.0 mL/kg dosing volume = 720 mg/kg). Therefore, the highest dose selected for mice was 360 mg/kg, which is approximately half the highest concentration possible based on solubility.

Male and female F344/N rats and B6C3F1/N mice were obtained from Taconic Farms, Inc. (Germantown, NY). On receipt, the rats and mice were approximately 4 weeks old. Animals were quarantined for 12 days and were 6 weeks old on the first day of the studies. Groups of five male and five female rats and mice received dermal applications of sodium thioglycolate in a vehicle of 95% ethanol:deionized water (1:1) at doses of 11.25, 22.5, 45, 90, or 180 mg/kg body weight (rats) or 22.5, 45, 90, 180, or 360 mg/kg (mice) 5 days per week for 16 (rats) or 17 (mice) days. Control animals were administered the vehicle only. Feed and water were available ad libitum. Rats and mice were housed individually. Clinical findings were recorded daily for rats and mice. The animals were weighed initially, on day 8, and at the end of the studies. Before the studies began, five male and five female rats and mice were randomly selected for parasite evaluation and gross observation for evidence of disease. All test results were negative. Details of the study design and animal maintenance are summarized in Table 1.

Table 1 Experimental Design and Materials and Methods in the Dermal Studies of Sodium Thioglycolate

Two-week Studies | Three-month Studies
Study Laboratory
BioReliance Corporation (Rockville, MD) | BioReliance Corporation (Rockville, MD)
Strain and Species
F344/N rats | F344/N rats
B6C3F1/N mice | B6C3F1/N mice
Animal Source
Taconic Farms, Inc. (Germantown, NY) | Taconic Farms, Inc. (Germantown, NY)
Time Held Before Studies
12 days | Rats: 13 (males) or 14 (females) days Mice: 16 (males) or 17 (females) days
Average Age When Studies Began
6 weeks | 5 to 6 weeks
Date of First Dose
January 16, 2001 | Rats: December 16, 2002 Mice: December 19, 2002
Duration of Dosing
Rats: 5 exposures per week for 16 calendar days Mice: 5 exposures per week for 17 calendar days | Core study (rats and mice): 5 exposures per week for 14 weeks Special study (rats): 5 exposures per week for 22 days
Date of Last Dose
Rats: January 31, 2001 Mice: February 1, 2001 | Rats: March 18, 2003 Mice: March 20, 2003
Necropsy Dates
Rats: February 1, 2001 Mice: February 2, 2001 | Rats: March 18 (males) or 19 (females), 2003 Mice: March 20 (males) or 21 (females), 2003
Average Age at Necropsy
8 to 9 weeks | 18 to 19 weeks
Size of Study Groups
5 males and 5 females | 10 males and 10 females
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights | Same as 2-week studies
Animals per Cage
1 | 1
Method of Animal Identification
Tail tattoo | Tail tattoo
Diet
NTP-2000 irradiated wafer diet (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, changed weekly | Same as 2-week studies, except meal form, changed weekly, except male rats changed twice weekly beginning January 24, 2003
Water
Tap water (Washington Suburban Sanitary Commission Potomac Plant) via automatic watering system (Edstrom Industries, Inc., Waterford, WI), available ad libitum | Same as 2-week studies
Cages
Solid-bottom polycarbonate (Lab Products, Inc., Seaford, DE), changed once a week | Same as 2-week studies
Bedding
Irradiated, heat-treated hardwood chips (P.J. Murphy Forest Products, Inc., Montville, NJ), changed once a week | Same as 2-week studies
Cage Filters
Remay 2016 (Snow Filtration, West Chester, OH), changed every 2 weeks | Same as 2-week studies
Racks
Stainless steel (Lab Products, Inc., Seaford, DE), changed every 2 weeks | Same as 2-week studies
Animal Room Environment
Temperature: 72° ± 3°F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Room air changes: 10/hour | Temperature: 72° ± 3°F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Room air changes: 10/hour
Doses
Rats: 0, 11.25, 22.5, 45, 90, or 180 mg/kg in 95% ethanol:deionized water (1:1), dosing volume 0.5 mL/kg Mice: 0, 22.5, 45, 90, 180, or 360 mg/kg in 95% ethanol:deionized water (1:1), dosing volume 2.0 mL/kg | Rats: 0, 11.25, 22.5, 45, 90 or 180 mg/kg in 95% ethanol:deionized water (1:1), dosing volume 0.5 mL/kg Mice: 0, 22.5, 45, 90, 180, or 360 mg/kg in 95% ethanol:deionized water (1:1), dosing volume 2.0 mL/kg
Type and Frequency of Observation
Observed twice daily; animals were weighed initially, on day 8, and at the end of the studies; clinical findings were recorded daily. | Observed twice daily; animals were weighed initially, weekly, and at the end of the studies; clinical findings and feed consumption were recorded weekly.
Method of Kill
Carbon dioxide asphyxiation | Same as 2-week studies
Necropsy
Necropsies were performed on all animals. Organs weighed were heart, right kidney, liver, lung, spleen, right testis, thymus, and thyroid gland. | Necropsies were performed on all core study animals. Organs weighed were heart, right kidney, liver, lung, spleen, right testis, thymus, and thyroid gland.
Clinical Pathology
None | Blood was collected from the retroorbital sinus of clinical pathology study rats on days 4 and 22 and from core study rats and mice at the end of the studies for hematology (rats and mice) and clinical chemistry (rats). Hematology: hematocrit; hemoglobin concentration; erythrocyte, reticulocyte, and platelet counts; mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; and leukocyte count and differentials Clinical chemistry: urea nitrogen, creatinine, total protein, albumin, alanine aminotransferase, alkaline phosphatase, creatine kinase, sorbitol dehydrogenase, total bile acids, globulin, albumin-globulin ratio, total cholesterol, free fatty acids, and 3-hydroxybutyrate
Histopathology
Histopathology was performed on all vehicle control rats and mice, 180 mg/kg rats, and 360 mg/kg mice. In addition to gross lesions and tissue masses, the following tissues were examined to a no-effect level: eyes, Harderian gland, kidney, liver, lung, pituitary gland, skin (site of application and control), spleen, stomach (forestomach and glandular), and thyroid gland. | Complete histopathology was performed on all vehicle control rats and mice, 180 mg/kg rats, and 360 mg/kg mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, eyes, gallbladder (mice only), Harderian gland, heart and aorta, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, liver, lung (with bronchus), lymph nodes (mandibular and mesenteric), mammary gland, nose, ovary, pancreas, pancreatic islets, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle, skin (site of application and control), spleen, stomach (forestomach and glandular), testis (with epididymis), thymus, thyroid gland, trachea, urinary bladder, and uterus. The skin was also examined in the remaining dosed groups.
Sperm Motility and Vaginal Cytology
None | At the end of the studies, sperm samples were collected from male animals exposed to 0, 45 (rats only), 90, 180, and 360 (mice only) mg/kg for sperm count and motility evaluations. The following parameters were evaluated: spermatid heads per testis and per gram testis, sperm counts, and epididymal spermatozoal motility and concentration. The left cauda, left epididymis, and left testis were weighed. Vaginal samples were collected for up to 12 consecutive days prior to the end of the studies from females exposed to 0, 45 (rats only), 90, 180, and 360 (mice only) mg/kg for vaginal cytology evaluations.

Necropsies were performed on all rats and mice. The heart, right kidney, liver, lung, spleen, right testis, thymus, and thyroid gland were weighed. Histopathologic examinations were performed on vehicle control rats and mice, 180 mg/kg rats, 360 mg/kg mice, and animals that died early. Table 1 lists the tissues and organs examined to a no-effect level.

## Three-month Studies

Male and female F344/N rats and B6C3F1/N mice were obtained from Taconic Farms, Inc. (Germantown, NY). On receipt, the rats were 4 weeks old and the mice were 3 weeks old. Rats were quarantined for 13 (males) or 14 (females) days and were 6 weeks old on the first day of the studies. Mice were quarantined for 16 (males) or 17 (females) days and were 6 weeks old on the first day of the studies. Before the studies began, five male and five female rats and mice were randomly selected for parasite evaluation and gross observation for evidence of disease. At the end of the studies, serologic analyses were performed on five male and five female vehicle control rats and sentinel mice using the protocols of the NTP Sentinel Animal Program (Appendix I). All test results were negative.

Groups of 10 male and 10 female core study rats and mice received dermal applications of sodium thioglycolate in a vehicle of 95% ethanol:deionized water (1:1) at doses of 11.25 (rats only), 22.5, 45, 90, 180, or 360 (mice only) mg/kg body weight 5 days per week for 3 months; the dosing volume was 0.5 mL/kg for rats and 2.0 mL/kg for mice. Additional groups of 10 male and 10 female rats designated for clinical pathology testing were administered the same doses for up to 22 days. Vehicle control rats and mice were administered the vehicle only. Doses were applied to the shaved dorsal skin from just posterior to the scapulae to the base of the tail. The dosing area was shaved weekly in both rats and mice. Feed and water were available ad libitum. Rats and mice were housed individually. All animal studies were conducted in an animal facility accredited by the Association for the Assessment and Accreditation of Laboratory Animal Care International. Studies were approved by the BioReliance Corporation (Rockville, MD) Animal Care and Use Committee and conducted in accordance with all relevant NTP animal care and use policies and applicable federal, state, and local regulations and guidelines. Clinical findings and feed consumption were recorded weekly for rats and mice. The animals were weighed initially, weekly, and at the end of the studies. Details of the study design and animal maintenance are summarized in Table 1. Information on feed composition and contaminants is provided in Appendix H.

Animals were anesthetized with 70% CO_2_:30% O_2_, and blood was collected from the retroorbital sinus of clinical pathology rats on days 4 and 22 and from core study rats at the end of the study for hematology and clinical chemistry analyses; blood was collected from the retroorbital sinus of mice at the end of the study for hematology analyses. Hematology parameters were measured using an ABX Penta C+ Analyzer (Horiba Instruments, Ann Arbor, MI). Clinical chemistry analyses were performed using a Hitachi 717 (Roche Diagnostics, Indianapolis, IN). The parameters measured are listed in Table 1.

At the end of the 3-month studies, samples were collected for sperm motility and vaginal cytology evaluations on core study rats and mice exposed to 0, 45 (rats only), 90, 180, and 360 (mice only) mg/kg. The parameters evaluated are listed in Table 1. For 12 consecutive days prior to scheduled terminal kill, the vaginal vaults of the females were moistened with saline, if necessary, and samples of vaginal fluid and cells were stained. Relative numbers of leukocytes, nucleated epithelial cells, and large squamous epithelial cells were determined and used to ascertain estrous cycle stage (i.e., diestrus, proestrus, estrus, and metestrus). Male animals were evaluated for sperm count and motility. The left testis and left epididymis were isolated and weighed. The tail of the epididymis (cauda epididymis) was then removed from the epididymal body (corpus epididymis) and weighed. Test yolk (rats) or modified Tyrode’s buffer (mice) was applied to slides, and a small incision was made at the distal border of the cauda epididymis. The sperm effluxing from the incision were dispersed in the buffer on the slides, and the numbers of motile and nonmotile spermatozoa were counted for five fields per slide by two observers. Following completion of sperm motility estimates, each left cauda epididymis was placed in buffered saline solution. Caudae were finely minced, and the tissue was incubated in the saline solution and then heat fixed at 65°C. Sperm density was then determined microscopically with the aid of a hemacytometer. To quantify spermatogenesis, the testicular spermatid head count was determined by removing the tunica albuginea and homogenizing the left testis in phosphate-buffered saline containing 10% dimethyl sulfoxide. Homogenization-resistant spermatid nuclei were counted with a hemacytometer.

Necropsies were performed on all core study animals. The heart, right kidney, liver, lung, spleen, right testis, thymus, and thyroid gland were weighed. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin, processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 μm, and stained with hematoxylin and eosin. Complete histopathologic examinations were performed by the study laboratory pathologist on the vehicle control groups of rats and mice, 180 mg/kg rats, and 360 mg/kg mice. The skin was examined in all remaining groups of rats and mice. Table 1 lists the tissues and organs routinely examined.

After a review of the laboratory reports and selected histopathology slides by a quality assessment (QA) pathologist, the findings and reviewed slides were submitted to a NTP Pathology Working Group (PWG) coordinator for a second independent review. Any inconsistencies in the diagnoses made by the study laboratory and QA pathologists were resolved by the NTP pathology peer review process. Final diagnoses for reviewed lesions represent a consensus of the PWG or a consensus between the study laboratory pathologist, NTP pathologist, QA pathologist(s), if any, and the PWG coordinator. Details of these review procedures have been described, in part, by Maronpot and Boorman28 and Boorman et al.29

## Statistical Methods

### Calculation and Analysis of Lesion Incidences

The incidences of lesions are presented in Appendix A as the numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. The Fisher exact test,30 a procedure based on the overall proportion of affected animals, was used to determine significance.

### Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between dosed and control groups in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett31 and Williams.32,33 Hematology, clinical chemistry, spermatid, and epididymal spermatozoal data, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley34 (as modified by Williams35) and Dunn.36 Jonckheere’s test37 was used to assess the significance of the dose-related trends and to determine whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic dose-related trend (Dunnett’s or Dunn’s test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey38 were examined by NTP personnel, and implausible values were eliminated from the analysis. Proportions of regular cycling females in each dosed group were compared to the control group using the Fisher exact test.30 Tests for extended periods of estrus, diestrus, metestrus, and proestrus, as well as skipped estrus and skipped diestrus, were constructed based on a Markov chain model proposed by Girard and Sager.39 For each dose group, a transition probability matrix was estimated for transitions among the proestrus, estrus, metestrus, and diestrus stages, with provision for extended stays within each stage as well as for skipping estrus or diestrus within a cycle. Equality of transition matrices among dose groups and between the control group and each dosed group was tested using chi-square statistics.

## Quality Assurance Methods

The 2-week and 3-month studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations.40 The Quality Assurance Unit of BioReliance Corporation performed audits and inspections of protocols, procedures, data, and reports throughout the course of the studies.

## Genetic Toxicology

### Salmonella typhimurium Mutagenicity Test Protocol

Testing was performed as reported by Zeiger et al.27 Sodium thioglycolate was sent to the laboratory as a coded aliquot from Radian Corporation (Austin, TX). It was incubated with the Salmonella typhimurium tester strains TA98, TA100, TA1535, and TA1537 either in buffer or S9 mix (metabolic activation enzymes and cofactors from Aroclor 1254-induced male Sprague Dawley rat or Syrian hamster liver) for 20 minutes at 37°C. Top agar supplemented with L-histidine and d-biotin was added, and the contents of the tubes were mixed and poured onto the surfaces of minimal glucose agar plates. Histidine-independent mutant colonies arising on these plates were counted following incubation for 2 days at 37°C.

Each trial consisted of triplicate plates of concurrent positive and negative controls and five doses of sodium thioglycolate. The high dose was limited by toxicity. All trials were repeated, except TA1535 with 10% rat S9.

In this assay, a positive response is defined as a reproducible, dose-related increase in histidine-independent (revertant) colonies in any one strain/activation combination. An equivocal response is defined as an increase in revertants that is not dose related, is not reproducible, or is not of sufficient magnitude to support a determination of mutagenicity. A negative response is obtained when no increase in revertant colonies is observed following chemical treatment. There is no minimum percentage or fold increase required for a chemical to be judged positive or weakly positive, although positive calls are typically reserved for increases in mutant colonies that are at least twofold over background.

### Mouse Peripheral Blood Micronucleus Test Protocol

A detailed discussion of this assay is presented by MacGregor et al.41 At the end of the 3-month toxicity study, peripheral blood samples were obtained from male and female mice. Smears were immediately prepared and fixed in absolute methanol. The methanol-fixed slides were stained with acridine orange and coded. Slides were scanned to determine the frequency of micronuclei in 2,000 normochromatic erythrocytes (NCEs) in each of five animals per dose group. In addition, the percentage of polychromatic erythrocytes in a population of 1,000 erythrocytes was determined as a measure of bone marrow toxicity.

The results were tabulated as the mean of the pooled results from all animals within a treatment group plus or minus the standard error of the mean. The frequency of micronucleated cells among NCEs was analyzed by a statistical software package that tested for increasing trend over dose groups with a one-tailed Cochran-Armitage trend test, followed by pairwise comparisons between each dosed group and the vehicle control group. In the presence of excess binomial variation, as detected by a binomial dispersion test, the binomial variance of the Cochran-Armitage test was adjusted upward in proportion to the excess variation. In the micronucleus test, an individual trial is considered positive if the trend test P value is less than or equal to 0.025 or if the P value for any single dosed group is less than or equal to 0.025 divided by the number of dosed groups. A final call of positive for micronucleus induction is preferably based on reproducibly positive trials (as noted above). Ultimately, the final call is determined by the scientific staff after considering the results of statistical analyses, the reproducibility of any effects observed, and the magnitudes of those effects.

### Evaluation Protocol

These are the basic guidelines for arriving at an overall assay result for assays performed by the National Toxicology Program. Statistical as well as biological factors are considered. For an individual assay, the statistical procedures for data analysis have been described in the preceding protocols. There have been instances, however, in which multiple samples of a chemical were tested in the same assay, and different results were obtained among these samples and/or among laboratories. Results from more than one aliquot or from more than one laboratory are not simply combined into an overall result. Rather, all the data are critically evaluated, particularly with regard to pertinent protocol variations, in determining the weight of evidence for an overall conclusion of chemical activity in an assay. In addition to multiple aliquots, the in vitro assays have another variable that must be considered in arriving at an overall test result. In vitro assays are conducted with and without exogenous metabolic activation. Results obtained in the absence of activation are not combined with results obtained in the presence of activation; each testing condition is evaluated separately. The results presented in the Abstract of this Toxicity Study Report represent a scientific judgment of the overall evidence for activity of the chemical in an assay.