# Introduction

Figure 1

Sodium Thioglycolate (CASRN 367-51-1; Chemical Formula: C_2_H_3_O_2_S•Na; Molecular Weight: 114.10)

Synonyms: Mercaptoacetic acid monosodium salt; mercaptoacetic acid, sodium salt; monosodium mercaptoacetate; sodium 2-mercaptoethanoate; sodium mercaptoacetate; sodium thioglycollate; thioglycolate sodium; thioglycolic acid, sodium salt; thioglycollic acid, sodium salt.

Trade names: Erhavit D, Mollescal SF.

## Chemical and Physical Properties

Sodium thioglycolate is a white powder with a melting point greater than 300°C. It appears as hygroscopic crystals with a characteristic odor. Sodium thioglycolate is soluble in water and slightly soluble in ethanol. It is combustible and discolors on exposure to air or iron.1

## Production, Use, and Human Exposure

Sodium thioglycolate is used primarily in the cosmetic industry as an antioxidant, depilating agent, hair waving/straightening agent, and reducing agent. Its primary cosmetic use is in depilatories. Sodium thioglycolate is also used as an analytical reagent and in bacteriology for the preparation of thioglycolate media.1-3

The production and use of sodium thioglycolate is linked to the production and use of thioglycolic acid. Thioglycolic acid can be prepared by the action of sodium sulfhydrate on sodium chloroacetate and by electrolysis of dithioglycollic acid from sodium sulfide and sodium chloroacetate.4 It is also formed by heating chloroacetic acid with potassium hydrogen sulfide.1 Thioglycolic acid and its salts and glyceryl esters are not known to occur naturally. No information was found in the literature identifying these chemicals in environmental media.

The annual United States production of thioglycolic acid was reported to be in the range of 10 to 50 million pounds for 2005; the most recent production numbers available for the sodium salt (10 to 500,000 pounds) are from 1994.^5^ While most of the volume of thioglycolic acid is used for industrial applications, the acid and its salts and glyceryl esters, including sodium thioglycolate, are used in cosmetic hair care products. Thioglycolates reduce the cystine disulfide linkages in the hair cortex, thereby weakening the keratin molecule. The predominant use of thioglycolic acid, ammonium thioglycolate, and glyceryl thioglycolate is in permanent wave and hair straightening products. Thioglycolic acid and ammonium thioglycolate concentrations in these products range from 7% to 19%, while glyceryl thioglycolate concentrations of 20% have been reported.6 Permanent wave products containing ammonium thioglycolate that are applied to the hair without heat may be expected to remain on the hair and scalp for as long as 10 to 40 minutes; products applied with heat usually contain thioglycolates other than the ammonium salt and are generally processed in 30 minutes but may remain on the head for up to 1 hour.6 Hair straightening products containing ammonium or ethanolamine thioglycolate or thioglycolic acid are usually applied to the hair for 45 minutes. Thioglycolic acid and its sodium and calcium salts are also used as depilatories. The concentrations of thioglycolic acid and calcium thioglycolate in depilatories are reported to be 2% to 5% and 5% to 7%, respectively.6,7 The sodium thioglycolate concentration in depilatories has been reported as 4%.6 Depilatory products containing thioglycolic acid and/or its salts are commonly applied to the face, legs, and arms, usually for a recommended maximum of 10 minutes, and may come in contact with the scalp and ocular and nasal mucosa.

The National Occupational Exposure Survey (NOES) conducted by the National Institute of Occupational Safety and Health (NIOSH)8 between 1981 and 1983 estimated that 30,055 workers were potentially exposed to thioglycolic acid in the workplace, that 41,132 workers were potentially exposed to ammonium thioglycolate in the workplace, and that 7,553 workers were potentially exposed to sodium thioglycolate in the workplace. The NOES database does not contain information on the frequency, level, or duration of exposure to workers of any chemical listed therein. Occupational exposure may be through inhalation of aerosols and dermal contact with these compounds at workplaces where they are produced or used. The general population may be exposed to these compounds by similar routes of exposure through the use of hair care products.7

## Regulatory Status

The American Conference of Governmental Industrial Hygienists (ACGIH)9 recommended a threshold limit value-time weighted average for thioglycolic acid of 1 ppm (3.8 mg/m^3^) with a skin notation to minimize the potential for dermal effects, eye irritation, and systemic effects. No short-term exposure limit (STEL) is recommended until additional toxicological data and industrial hygiene experience become available to determine what the STEL should be. The recommended exposure limit for thioglycolic acid is 1 ppm (4 mg/m^3^), with a skin notation, averaged over a 10-hour work shift.10

## Absorption, Distribution, Metabolism, and Excretion

### Experimental Animals

Freeman et al.11 investigated the dermal absorption of ^35^S-sodium thioglycolate using male rabbits (strain not specified). A 25.0% solution of ^35^S-thioglycolic acid (330 mg/kg) was applied to the dorsal skin. After 1 hour, 5% to 8% of the applied dose was excreted (measured as sulfur excretion), indicating rapid absorption from the skin. After 5 hours, 30% to 40% of the applied dose was excreted in the urine. Additional male rabbits receiving a dermal application of 660 mg/kg excreted 7% to 24% of the applied dose in 4 hours. Although it appears that no more thioglycolate was absorbed and excreted when the higher dose was applied, rabbits receiving 600 mg/kg died within 24 hours. After intravenous injection of 70, 80, or 123 mg/kg to rabbits, 60% to 80% of the doses were excreted in the urine within 24 hours.11 The test substance was excreted mostly as organic sulfate and neutral sulfur. The distribution and excretion of ^35^S-thioglycolic acid were evaluated in adult male New Zealand rabbits given 100 or 200 mg/kg doses of ^35^S-thioglycolic acid by intraperitoneal injection.12 After 24 hours, 84% to 93% of the administered doses were excreted in the urine, and most of the radioactivity appeared in the neutral sulfate fraction. A single topical application of sodium ^35^S-thioglycolate in Triton^®^ X-200 (1.0 mL/kg) to rabbits resulted in 16% of the radiolabel excreted after 24 hours, 4.5% after 48 hours, and 1.84% after 72 hours.13 After 4 days of topical administration, 24-hour urinary radioactivity peaked on day 4, with measurable radioactivity still detected on day 7. A single rabbit received sodium ^35^S-thioglycolate in Triton^®^ X-200 at 2.0 mL/kg per day for 7 days. The initial 24-hour urinary ^35^S recovery was 18.5% of the dose, with recovery falling to 4.7% by the seventh application. The animal died the next day.

Rats administered ^35^S-sodium thioglycolate intraperitoneally at doses of 12.5 to 75 mg/kg excreted 60% to 100% of the dose within 24 hours; 29% to 72% of the administered dose was excreted as inorganic sulfate.11 The pulmonary excretion of hydrogen disulfide was not noted up to 10 hours after intraperitoneal injection of a rat with 150 mg/kg of sodium thioglycolate.11 In a similar study where Holtzman rats were administered 100 mg/kg ^35^S-thioglycolic acid via intravenous or intraperitoneal injection, similar to rabbits, 82% or 91% of the administered dose was excreted in urine 24 hours after administration.12 In an animal injected intravenously with 50 mg/kg ^35^S-thioglycolic acid, the highest radioactivity 2 hours postinjection was observed in small intestine and kidneys. Following injection of 100 mg/kg, the rate of disappearance of radioactivity in blood was rapid with less than 3% radioactivity left 1 hour postinjection. In a subsequent study, 100 to 150 mg thioglycolic acid/kg administered intraperitoneally to rats led to significant urinary excretion of dithioglycolic acid (average of 28% of the dose) at 24 hours postinjection. Only negligible concentrations of thioglycolate were detected, suggesting the oxidation of thiols to disulfides.

The distribution of radioactivity in a female monkey was determined after intravenous injection of 300 mg/kg ^35^S-sodium thioglycolate.11 The greatest amount of radioactivity was found in the kidney, lung, and spleen 10 hours after injection, at which time the animal died. The monkey excreted thioglycolate mostly in the neutral sulfur fraction.

### Humans

No data on the absorption, distribution, metabolism, or excretion of sodium thioglycolate in humans were found in the literature.

## Toxicity

### Experimental Animals

Exposure to sodium thioglycolate through oral dosing, intraperitoneal injection, or intravenous injection has been shown to result in convulsion, dyspnea, and death in studies using mice, rats, monkeys, and dogs.14 The oral LD_50_ for sodium thioglycolate in fasted female CAF_1_ mice was reported to be 504 mg/kg.14 The intraperitoneal LD_50_ was 505 mg/kg for fasted female CAF_1_ mice,14 200 to 300 mg/kg for CF_1_ mice,15 and 126 mg/kg for young adult, fasted male Osborne-Mendel rats.14 The intravenous LD_50_ was 422 mg/kg for mice.16 The lowest lethal dose after intravenous injection was 100 mg/kg in rabbits,16 500 mg/kg in dogs,14 and 300 mg/kg in a female monkey.14 Sodium thioglycolate resulted in tremor, hypermotility, diarrhea, emesis, and convulsions in the dogs and emesis and coma in the monkey.14

Topical administration of sodium thioglycolate to rabbits at 0.600 N thioglycolate (pH 9.31) in 4% Triton^®^ X-200 at 2.0 to 2.5 mg/mL resulted in an LD_50_ of 1.69 ± 0.11 mL/kg per day, with an average of eight applications prior to death.13

Five male weanling Osborne-Mendel rats were injected intraperitoneally for 5 days a week with sodium thioglycolate at doses of 25, 50, 75, 100, or 125 mg/kg for 12 weeks.14 The rats in the higher dose groups exhibited lacrimation, apparent increased peristalsis of the gastrointestinal tract followed by a period of intermittent convulsions, and then dyspnea and death with convulsions.

Sodium thioglycolate was administered intraperitoneally (100 mg/kg as a 5% solution) to five male weanling Osborne-Mendel rats that were either in a “non-diabetic” or chemically induced “diabetic” state.14 Injections were given 5 days per week during a 24-week period. At the end of the 24-week period, there was no significant difference in weight gain between the treated and control groups. No significant gross lesions were observed at necropsy.

Sodium thioglycolate blocks fatty acid oxidation at different levels in the metabolic pathway and stimulates feed consumption in rats and mice when fed a fat-supplemented diet.17 Male Sprague Dawley rats exhibited three to fourfold higher feed consumption when given a medium-fat diet (18% fat) after an intraperitoneal injection of 46 mg/kg (400 µmol/kg) sodium thioglycolate.18 Another study reported that rats maintained on low-, medium-, or high-fat diets (4.3%, 13.5%, or 66.4%, respectively) ate significantly more feed after a single intraperitoneal dose of 69 mg/kg (600 µmol/kg) sodium thioglycolate.19 In another study, increases in feed consumption were observed in rats on medium (18%) but not low-fat (3.3%) diets20; 6 hours after injection, plasma free fatty acid concentrations were threefold greater and plasma 3-hydroxybutyrate and acetoacetate concentrations were significantly decreased in rats on a medium-fat diet compared to controls, indicating that fatty acid oxidation was inhibited. A robust summary of an unpublished oral gavage subchronic study in Sprague Dawley rats also reports increased feed consumption, increased fatty acids, and decreased 3-hydroxybutyrate and glucose in plasma, as well as increased alanine aminotransferase and urea in plasma and an increased incidence of minimal to slight periportal hepatocellular microvacuolation.21

Six hours after an intravenous injection of 175 mg sodium thioglycolate/kg to rabbits, blood sugar concentrations dropped to 55% of their initial value.14 In rats, this decrease was 65% compared to controls and occurred 5 to 6 hours after an intraperitoneal injection of 150 mg/kg. Mice administered 630 mg/kg intraperitoneally had a 70% decrease in hepatic glycogen concentrations.

### Humans

Exposure to ammonium thioglycolate and glyceryl thioglycolate has been shown to result in skin irritation and sensitization.15 The irritant capacity of ammonium thioglycolate solutions depends on concentration of the reagent (greater than 7%), duration of exposure, and formulation/basicity of the solution; for example, cold wave formulations are more irritating. Single applications of 6.5% or 7.0% ammonium thioglycolate and repeated applications of 6.5% ammonium thioglycolate (applied daily for 40 to 60 minutes over a period of 2 months) did not induce skin irritation in normal subjects. However, repeated applications (24 hours daily for 21 days) of permanent wave solutions containing 7.1% ammonium thioglycolate, 5.0% urea, and 1.2% ammonium hydroxide caused strong skin irritation reactions in normal subjects. Ammonium thioglycolate (6.0%) was classified as a skin irritant and sensitizer after single applications were made to subjects with a history of dermatitis, cutaneous disturbances, and/or a history of use of cold wave formulations, such as hairdressers. The sensitizing activity of ammonium thioglycolate is much lower in normal subjects, who display weak sensitization reactions with repeated exposures to greater concentrations of the reagent.

The irritant capacity of glyceryl thioglycolate solutions is greater than that of ammonium thioglycolate solutions. A 21-day dermal study of a 2.0% aqueous solution of glyceryl thioglycolate induced skin irritation in all subjects tested.15 A challenge application 10 days after completion of the test induced an allergic response in some of these subjects. However, glyceryl thioglycolate was not an irritant at concentrations of 14.0% to 15.4% in normal subjects who received two 48-hour patch applications separated by a 14-day nontreatment period. Skin sensitization and allergic contact dermatitis were widely observed in hairdressers and clients who received single applications of 0.25% to 2.5% glyceryl thioglycolate in a 48-hour patch test.

A safety assessment by the Cosmetic Ingredient Review6 of thioglycolic acid, sodium thioglycolate, and other thioglycolic acid derivatives concluded that without adequate skin protection, hairdressers should avoid repeated applications of cosmetic products containing ammonium or glyceryl thioglycolate to multiple clients over a period of time. In addition, the Cosmetic, Toiletry, and Fragrance Association (CTFA)2 concluded that hairdressers should avoid skin contact and minimize consumer skin exposure to these compounds.

## Reproductive and Developmental Toxicity

Animal studies evaluating developmental effects of thioglycolate exposure are limited. The National Toxicology Program completed developmental toxicity studies for sodium thioglycolate using Sprague Dawley rats and New Zealand White rabbits.22 Sodium thioglycolate was administered by unoccluded topical application to pregnant Sprague Dawley rats (25 per group) at doses of 0, 50, 100, or 200 mg/kg per day on gestation day (GD) 6 to 19. One of 20 pregnant 200 mg/kg rats died on GD 18. Dams dosed with 200 mg/kg had decreased body weights and weight gain and increased relative water consumption. Treatment-related increases in feed consumption and changes at the application site occurred at all doses in the absence of increased body weights or body weight change. Male and female fetal body weights per litter were also decreased at 200 mg/kg. New Zealand White rabbits (24 per group) were dosed dermally with sodium thioglycolate at doses of 0, 10, 15, 25, or 65 mg/kg per day on GD 6 to 29. Maternal toxicity at the site of application (erythema) was observed in all dosed groups. Maternal and fetal body weights were not affected. Sodium thioglycolate did not affect resorptions, fetal viability, or fetal external, visceral, or skeletal alterations in either species.

A dose range-finding embryo-fetal toxicity study of ammonium thioglycolate was carried out in Wistar rats (Walker23,24 cited in Tyl et al.22). The test chemical was administered by oral gavage once daily on GD 6 through 19 at doses of 0, 1, 10, 50, 100, or 150 mg/kg per day to five sperm-positive females per group. All five 150 mg/kg females died, and three of five 100 mg/kg females died. Body weight gain was decreased from GD 6 through 10 in females dosed with 50, 100, or 150 mg/kg per day. Fetal loss was increased in the two surviving 100 mg/kg dams. Based on this range-finding study, a definitive developmental toxicity study of ammonium thioglycolate was carried out in Wistar rats (Walker23,24 cited in Tyl et al.22). Ammonium thioglycolate was administered by oral gavage at doses of 0, 3, 15, or 75 mg/kg per day to 25 sperm-positive females per group on GD 6 through 19. Two 75 mg/kg dams died on GD 20. Maternal body weights and feed and water consumption were unaffected by treatment. The number of ovarian corpora lutea, uterine implantations, early and late resorptions, dead fetuses, live fetuses per litter, sex distribution, fetal body weights, and frequency of fetal malformations per litter were all unaffected by treatment.

No reproductive toxicity studies of sodium thioglycolate in animals were found in the literature.

## Carcinogenicity

### Experimental Animals

There was no evidence of carcinogenicity in female Swiss mice or female rabbits (strain not specified) that received dermal applications of 0.02 mL of 1% or 2% sodium thioglycolate solutions in acetone twice per week when compared to control groups.25 Sodium thioglycolate was applied to the shaved interscapular skin of 45 to 49 mice and to the inside of the left ear of five rabbits. Mice were allowed to die spontaneously or were killed when moribund, and rabbits were killed at week 85. Incidences of neoplasms in dosed and control mice were not significantly different. No neoplasms were observed in rabbits treated with sodium thioglycolate. No significant change was observed in the survival of dosed mice or rabbits.

### Humans

No epidemiology studies of thioglycolic acid, its ammonium, calcium, or sodium salts, or its glyceryl esters were found in the literature.

## Genetic Toxicity

Sodium thioglycolate was not mutagenic at concentrations up to 3,600 μg/plate in Salmonella typhimurium strains TA98, TA100, TA1535, TA1537, or TA1538, with or without rat or hamster liver S9 metabolic activation enzymes.26,27 No increases were reported in the frequencies of micronucleated erythrocytes in bone marrow of male or female NMRI mice administered 114 or 285 mg sodium thioglycolate/kg intraperitoneally.26 However, the lack of experimental detail makes it difficult to determine whether the test protocol was adequate to detect the in vivo mutagenic potential of sodium thioglycolate. Sodium thioglycolate administered by feeding in 5% sucrose was tested for induction of sex-linked recessive lethal mutations in germ cells of male Drosophila melanogaster; results were negative.15,26

## Study Rationale

Sodium thioglycolate was nominated by the National Cancer Institute for toxicology studies due to its high production volume and widespread occupational and consumer exposure to thioglycolic acid and its salts and esters, including significant female exposure in personal care products.