# Appendix I Sentinel Animal Program

## I.1 Methods

Rodents used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that may affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicologic evaluation of test compounds. Under this program, the disease state of the rodents is monitored via sera or feces from extra (sentinel) animals in the study rooms. The sentinel animals and the study animals are subject to identical environmental conditions. Furthermore, the sentinel animals come from the same production source and weanling groups as the animals used for the studies of test compounds.

Blood samples were collected from each animal and allowed to clot, and the serum was separated. Additionally, fecal samples were collected and tested for Helicobacter species. All samples were processed appropriately and evaluated for the presence of pathogens. The laboratory methods and agents for which testing was performed are tabulated below; the times at which samples were collected during the studies are also listed.

Table I-1 Laboratory Methods and Agents Tested for in the Sentinel Animal Program

Method and Test | Time of Collection
Rats
3-month study
ELISA
PVM (pneumonia virus of mice) | Study termination
RCV/SDA (rat coronavirus/sialodacryoadenitis virus) | Study termination
Sendai | Study termination
Immunofluorescence Assay
Parvovirus | Study termination
Mice
3-month study
ELISA
Ectromelia virus | Study termination
EDIM (epizootic diarrhea of infant mice) | Study termination
GDVII (mouse encephalomyelitis virus) | Study termination
LCM (lymphocytic choriomeningitis virus) | Study termination
Mouse adenoma virus-FL | Study termination
MHV (mouse hepatitis virus) | Study termination
PVM | Study termination
Reovirus | Study termination
Sendai | Study termination
Immunofluorescence Assay
Parvovirus | Study termination

## I.2 Results

All test results were negative.