# Appendix G Feed Consumption

Table G-1 Feed Consumption for Male Rats in the Three-month Dermal Study of Sodium Thioglycolate^a^

| Vehicle Control | | 11.25 mg/kg | | 22.5 mg/kg
Week | Feed (g/day) | N/M | Feed (g/day) | N/M | Feed (g/day) | N/M
2 | 16.9 | 10/10 | 16.6 | 10/10 | 15.7 | 10/10
3 | 17.8 | 10/10 | 15.9 | 10/10 | 17.6 | 10/10
4 | 19.3 | 10/10 | 19.2 | 10/10 | 19.7 | 10/10
5 | 20.5 | 10/10 | 20.2 | 10/10 | 20.6 | 10/10
6 | 25.3 | 10/20 | 23.6 | 10/20 | 24.0 | 10/20
7 | 28.4 | 10/20 | 27.6 | 10/20 | 28.6 | 10/20
8 | 24.3 | 10/20 | 22.7 | 10/20 | 22.9 | 10/20
9 | 27.2 | 10/20 | 27.8 | 10/20 | 27.5 | 10/20
10 | 26.2 | 10/20 | 23.8 | 10/20 | 25.0 | 10/20
11 | 26.3 | 10/20 | 26.0 | 10/20 | 29.4 | 10/20
12 | 24.9 | 10/20 | 24.1 | 10/20 | 26.5 | 10/20
13 | 27.5 | 10/20 | 26.9 | 10/20 | 28.2 | 10/20
14 | 24.2 | 10/10 | 22.4 | 10/10 | 23.9 | 10/10
| 45 mg/kg | | 90 mg/kg | | 180 mg/kg
2 | 16.1 | 10/10 | 14.9 | 10/10 | 15.4 | 10/10
3 | 19.7 | 10/10 | 18.3 | 10/10 | 19.9 | 10/10
4 | 20.2 | 10/10 | 19.1 | 10/10 | 19.5 | 10/10
5 | 21.2 | 10/10 | 20.4 | 10/10 | 21.5 | 10/10
6 | 24.1 | 10/20 | 23.6 | 10/20 | 23.6 | 10/20
7 | 30.7 | 10/20 | 27.5 | 10/20 | 27.8 | 10/20
8 | 25.6 | 10/20 | 22.8 | 10/20 | 23.0 | 10/20
9 | 27.0 | 10/20 | 25.2 | 10/20 | 26.1 | 10/20
10 | 26.1 | 10/20 | 22.5 | 10/20 | 24.3 | 10/20
11 | 28.9 | 10/20 | 25.4 | 10/20 | 24.8 | 10/20
12 | 24.8 | 10/20 | 24.5 | 10/20 | 24.6 | 10/20
13 | 30.9 | 10/20 | 26.1 | 10/20 | 26.1 | 10/20
14 | 25.5 | 10/10 | 21.2 | 10/10 | 23.0 | 10/10

^a^ Feed = average feed consumption in grams/animal per day; N = number of animals; M = number of feed consumption measurements per week.

Table G-2 Feed Consumption for Female Rats in the Three-month Dermal Study of Sodium Thioglycolate^a^

| Vehicle Control | | 11.25 mg/kg | | 22.5 mg/kg
Week | Feed (g/day) | N/M | Feed (g/day) | N/M | Feed (g/day) | N/M
2 | 13.8 | 10/10 | 13.2 | 10/10 | 13.9 | 10/10
3 | 15.4 | 10/10 | 16.4 | 10/10 | 17.1 | 10/10
4 | 16.0 | 10/10 | 16.3 | 10/10 | 16.4 | 10/10
5 | 14.9 | 10/10 | 14.9 | 10/10 | 14.9 | 10/10
6 | 16.7 | 10/10 | 18.3 | 10/10 | 17.6 | 10/10
7 | 15.8 | 10/10 | 15.3 | 10/10 | 17.4 | 10/10
8 | 18.9 | 10/10 | 19.8 | 10/10 | 20.5 | 10/10
9 | 16.4 | 10/10 | 18.5 | 10/10 | 20.0 | 10/10
10 | 17.0 | 10/10 | 18.6 | 10/10 | 20.6 | 10/10
11 | 14.9 | 10/10 | 16.6 | 10/10 | 18.5 | 10/10
12 | 19.2 | 10/10 | 17.8 | 10/10 | 18.1 | 10/10
13 | 15.6 | 10/10 | 16.5 | 10/10 | 18.5 | 10/10
14 | 16.0 | 10/10 | 16.1 | 10/10 | 18.2 | 10/10
| 45 mg/kg | | 90 mg/kg | | 180 mg/kg
2 | 13.6 | 10/10 | 13.1 | 10/10 | 12.1 | 10/10
3 | 16.3 | 10/10 | 16.9 | 10/10 | 15.9 | 10/10
4 | 16.2 | 10/10 | 15.3 | 10/10 | 14.0 | 10/10
5 | 16.0 | 10/10 | 14.7 | 10/10 | 14.5 | 10/10
6 | 19.1 | 10/10 | 16.0 | 10/10 | 18.3 | 10/10
7 | 18.7 | 10/10 | 16.8 | 10/10 | 15.9 | 10/10
8 | 21.2 | 10/10 | 15.9 | 10/10 | 15.2 | 10/10
9 | 19.1 | 10/10 | 17.0 | 10/10 | 16.1 | 10/10
10 | 18.7 | 10/10 | 17.4 | 10/10 | 17.5 | 10/10
11 | 17.7 | 10/10 | 15.9 | 10/10 | 16.5 | 10/10
12 | 17.7 | 10/10 | 16.6 | 10/10 | 18.5 | 10/10
13 | 20.4 | 10/10 | 18.9 | 10/10 | 20.1 | 10/10
14 | 17.6 | 10/10 | 16.6 | 10/10 | 16.3 | 10/10

^a^ Feed = average feed consumption in grams/animal per day; N = number of animals; M = number of feed consumption measurements per week.

Table G-3 Feed Consumption for Male Mice in the Three-month Dermal Study of Sodium Thioglycolate^a^

| Vehicle Control | | 22.5 mg/kg | | 45 mg/kg
Week | Feed (g/day) | N/M | Feed (g/day) | N/M | Feed (g/day) | N/M
2 | 5.7 | 10/10 | 5.5 | 10/10 | 5.4 | 10/10
3 | 6.6 | 10/10 | 7.0 | 10/10 | 6.4 | 10/10
4 | 6.9 | 10/10 | 6.6 | 10/10 | 7.0 | 10/10
5 | 6.3 | 10/10 | 6.6 | 10/10 | 7.0 | 10/10
6 | 6.7 | 10/10 | 6.4 | 10/10 | 7.0 | 10/10
7 | 6.1 | 10/10 | 6.7 | 10/10 | 6.3 | 10/10
8 | 5.8 | 10/10 | 6.5 | 10/10 | 6.2 | 10/10
9 | 6.6 | 10/10 | 6.4 | 10/10 | 6.9 | 10/10
10 | 7.0 | 10/10 | 6.6 | 10/10 | 7.4 | 10/10
11 | 6.2 | 10/10 | 6.2 | 10/10 | 7.2 | 10/10
12 | 6.4 | 10/10 | 6.2 | 10/10 | 6.3 | 10/10
13 | 6.5 | 10/10 | 6.4 | 10/10 | 6.2 | 9/9
14 | 6.3 | 10/10 | 6.4 | 10/10 | 6.4 | 10/10
| 90 mg/kg | | 180 mg/kg | | 360 mg/kg
2 | 5.4 | 10/10 | 6.1 | 10/10 | 6.3 | 10/10
3 | 6.6 | 10/10 | 6.2 | 10/10 | 7.0 | 10/10
4 | 6.3 | 10/10 | 6.3 | 10/10 | 6.8 | 10/10
5 | 5.7 | 10/10 | 6.4 | 10/10 | 6.9 | 10/10
6 | 6.2 | 9/9 | 6.4 | 10/10 | 7.8 | 10/10
7 | 6.0 | 10/10 | 6.4 | 10/10 | 6.1 | 10/10
8 | 5.8 | 10/10 | 6.4 | 10/10 | 7.1 | 10/10
9 | 6.4 | 10/10 | 6.6 | 10/10 | 6.8 | 10/10
10 | 6.2 | 10/10 | 6.6 | 10/10 | 7.1 | 10/10
11 | 6.4 | 10/10 | 6.1 | 10/10 | 7.8 | 10/10
12 | 5.8 | 10/10 | 6.9 | 10/10 | 7.1 | 10/10
13 | 7.0 | 10/10 | 6.7 | 10/10 | 7.3 | 10/10
14 | 6.0 | 10/10 | 6.5 | 10/10 | 7.1 | 10/10

^a^ Feed = average feed consumption in grams/animal per day; N = number of animals; M = number of feed consumption measurements per week.

Table G-4 Feed Consumption for Female Mice in the Three-month Dermal Study of Sodium Thioglycolate^a^

| Vehicle Control | | 22.5 mg/kg | | 45 mg/kg
Week | Feed (g/day) | N/M | Feed (g/day) | N/M | Feed (g/day) | N/M
2 | 5.6 | 10/10 | 6.1 | 10/10 | 5.8 | 10/10
3 | 7.7 | 10/10 | 6.6 | 10/10 | 7.2 | 10/10
4 | 6.7 | 10/10 | 6.3 | 10/10 | 7.0 | 10/10
5 | 7.0 | 10/10 | 7.6 | 10/10 | 6.2 | 10/10
6 | 6.5 | 10/10 | 6.0 | 10/10 | 6.6 | 9/9
7 | 6.1 | 10/10 | 6.3 | 10/10 | 5.9 | 10/10
8 | 6.4 | 10/10 | 5.7 | 10/10 | 6.9 | 10/10
9 | 7.0 | 10/10 | 6.2 | 10/10 | 6.9 | 10/10
10 | 6.8 | 10/10 | 6.8 | 10/10 | 6.7 | 10/10
11 | 7.0 | 10/10 | 6.7 | 10/10 | 6.9 | 10/10
12 | 6.7 | 10/10 | 6.5 | 10/10 | 6.5 | 10/10
13 | 7.2 | 10/10 | 7.3 | 10/10 | 8.0 | 10/10
14 | 7.0 | 10/10 | 7.4 | 10/10 | 7.2 | 10/10
| 90 mg/kg | | 180 mg/kg | | 360 mg/kg
2 | 5.6 | 10/10 | 5.1 | 10/10 | 6.3 | 10/10
3 | 6.8 | 10/10 | 6.1 | 10/10 | 6.6 | 10/10
4 | 6.7 | 10/10 | 7.0 | 10/10 | 7.1 | 10/10
5 | 6.7 | 10/10 | 7.2 | 10/10 | 6.9 | 10/10
6 | 6.8 | 10/10 | 6.8 | 10/10 | 6.9 | 10/10
7 | 7.0 | 10/10 | 6.3 | 10/10 | 6.6 | 10/10
8 | 6.3 | 10/10 | 7.6 | 10/10 | 6.6 | 10/10
9 | 7.8 | 10/10 | 7.4 | 10/10 | 7.0 | 10/10
10 | 6.5 | 10/10 | 7.0 | 10/10 | 7.0 | 10/10
11 | 7.0 | 10/10 | 7.3 | 10/10 | 7.4 | 10/10
12 | 6.9 | 10/10 | 7.0 | 10/10 | 7.5 | 10/10
13 | 7.8 | 10/10 | 7.7 | 10/10 | 7.7 | 10/10
14 | 7.2 | 10/10 | 7.7 | 10/10 | 7.7 | 10/10

^a^ Feed = average feed consumption in grams/animal per day; N = number of animals; M = number of feed consumption measurements per week.