# Appendix F Chemical Characterization and Dose Formulation Studies

## F.1 Procurement and Characterization

### F.1.1 Sodium Thioglycolate

Sodium thioglycolate was obtained by the analytical chemistry laboratory (Midwest Research Institute, Kansas City, MO) from Sigma Chemical Company (Columbus, OH) in one lot (88H1166) that was used in the 2-week and 3-month studies. Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory. Reports on analyses performed in support of the sodium thioglycolate studies are on file at the National Institute of Environmental Health Sciences.

Lot 88H1166 of the chemical, a white powder, was identified as sodium thioglycolate by infrared and proton and carbon-13 nuclear magnetic resonance (NMR) spectroscopy. The infrared spectrum was consistent with a literature spectrum43 of sodium thioglycolate, and NMR spectra were consistent with the proposed structure of the test article. The infrared and NMR spectra are presented in Figure F-1, Figure F-2, and Figure F-3.

The purity of lot 88H1166 was determined by ion chromatography using a Dionex LC20 chromatograph (Dionex Corporation, Sunnyvale, CA) with conductivity detection, a Dionex IonPac^®^ AS11-HC column (25 cm × 4 mm, 9 μm particle size), and a mobile phase of 17.5 mM aqueous sodium hydroxide at an isocratic flow rate of 1.0 mL/minute. Purity assays indicated one major peak and three impurities with a combined area of approximately 1% relative to the total peak area. The overall purity of lot 88H1166 was determined to be approximately 99%.

Stability studies of a different lot of the bulk chemical were performed by the analytical chemistry laboratory using the ion chromatography system previously described. These studies indicated that sodium thioglycolate was stable as a bulk chemical for 14 days when stored protected from light frozen (−20°C), refrigerated (5°C), and heated (60°C) but not at ambient (25°C) temperature. To ensure stability, the bulk chemical was stored under a headspace of inert gas at less than or equal to −20°C, protected from light, in amber glass bottles. The analytical chemistry laboratory reanalyzed the bulk chemical at the end of the 3-month study by ion chromatography using the system previously described. No degradation of the bulk chemical was detected.

### F.1.2 95% Ethanol

95% Ethanol, a clear liquid, was obtained from Pharmco Products, Inc. (Brookfield, CT), in two lots (P1107 and R8092); lot P1107 was used in the 2-week studies, and lot R8092 was used in the 3-month studies. The study laboratory (BioReliance Corporation, Rockville, MD) identified lot R8092 of the chemical as ethanol by infrared spectroscopy and determined the purities of both lots of the chemical using gas chromatography; no impurity peaks were noted.

## F.2 Preparation and Analysis of Dose Formulations

The dose formulations were prepared on three separate days during the 2-week studies and approximately weekly during the 3-month studies by mixing sodium thioglycolate and the vehicle [95% ethanol:deionized water (1:1)] to give the required concentration (Table F-1). The dose formulations were stored under an inert gas headspace at 2° to 8°C in amber vials sealed with Teflon^®^-lined septa and aluminum seals for up to 10 days. Fresh dosing bottles were opened each day.

Stability studies of a 3.1 mg/mL dose formulation of a different lot were performed by the analytical chemistry laboratory using ion chromatography by the system previously described. Stability was confirmed for at least 10 days for dose formulations stored at approximately 5°C in sealed amber vials and for at least 3 hours for dose formulations exposed to ambient temperature and light.

Periodic analyses of samples of the dose formulations of sodium thioglycolate were conducted by the analytical chemistry laboratory because ion chromatography was not available at the study laboratory. Samples of formulations were collected in amber glass vials under inert gas headspace and shipped on dry ice for overnight delivery to the analytical chemistry laboratory. Animal room samples were collected similarly following dosing on the last day of the use period. During the 2-week studies, the dose formulations were analyzed twice; nine of 10 dose formulations for rats and eight of 10 dose formulations for mice were within 10% of the target concentrations (Table F-2). For animal room samples analyzed, three of five for rats and three of five for mice were within 10% of the target concentrations. During the 3-month studies, the dose formulations were analyzed at the beginning, midpoint, and end of the studies; animal room samples of these dose formulations were also analyzed (Table F-3). Of the dose formulations analyzed, all 15 for rats and all 15 for mice were within 10% of the target concentrations; two of 15 animal room samples analyzed for rats and four of 15 animal room samples analyzed for mice were within 10% of the target concentrations. Declines in animal room sample concentrations of sodium thioglycolate were attributed to degradation during the additional time required for shipping and analyzing the samples at the end of the use period.

Table F-1 Preparation and Storage of Dose Formulations in the Dermal Studies of Sodium Thioglycolate

Two-week Studies | Three-month Studies
Preparation
The vehicle was prepared by combining equal volumes of 95% ethanol and deionized water. The dose formulations were prepared by dissolving a weighed amount of sodium thioglycolate in a measured volume of the vehicle. Magnetic stirring was used to ensure that the test article was completely dissolved. Dose formulations were prepared three times. Fresh dosing bottles were opened each day. | The vehicle was prepared by combining equal volumes of 95% ethanol and deionized water. The dose formulations were prepared by dissolving a weighed amount of sodium thioglycolate in a measured volume of the vehicle; brief sonication and magnetic stirring were used to ensure that the test article was completely dissolved. Dose formulations were prepared approximately weekly. Fresh dosing bottles were opened each day.
Chemical Lot Number
88H1166 | 88H1166
Maximum Storage Time
10 days | 10 days
Storage Conditions
Stored at 2° to 8°C in amber vials sealed with Teflon^®^-lined septa and aluminum seals after purging the headspace with inert gas | Stored at 2° to 8°C in amber vials sealed with Teflon^®^-lined septa and aluminum seals after purging the headspace with inert gas
Study Laboratory
BioReliance Corporation (Rockville, MD) | BioReliance Corporation (Rockville, MD)

Table F-2 Results of Analyses of Dose Formulations Administered to Rats and Mice in the Two-week Dermal Studies of Sodium Thioglycolate

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration^a^ (mg/mL) | Difference from Target (%)
Rats
January 8, 2001 | January 10, 2001 | 22.5 | 23.9 | +6
| | 45 | 46.5 | +3
| | 90 | 92.7 | +3
| | 180 | 182.4 | +1
| | 360 | 377.5 | +5
January 25, 2001 | February 7, 2001 | 22.5 | 23.3 | +4
| | 45 | 47.4 | +5
| | 90 | 98.1 | +9
| | 180 | 202.5 | +13
| | 360 | 395.2 | +10
| February 7, 2001^b^ | 22.5 | 21.2 | −6
| | 45 | 45.9 | +2
| | 90 | 96.9 | +8
| | 180 | 204.1 | +13
| | 360 | 405.7 | +13
Mice
January 8, 2001 | January 10, 2001 | 11.25 | 11.46 | +2
| | 22.5 | 23.9 | +6
| | 45 | 46.5 | +3
| | 90 | 92.7 | +3
| | 180 | 182.4 | +1
January 25, 2001 | February 7, 2001 | 11.25 | 10.03 | −11
| | 22.5 | 23.3 | +4
| | 45 | 47.4 | +5
| | 90 | 98.1 | +9
| | 180 | 202.5 | +13
| February 7, 2001^b^ | 11.25 | 9.34 | −17
| | 22.5 | 20.6 | −8
| | 45 | 41.3 | −8
| | 90 | 91.7 | +2
| | 180 | 202.6 | +13

^a^ Results of duplicate analyses. For rats, dosing volume = 0.5 mL/kg; 22.5 mg/mL = 11.25 mg/kg, 45 mg/mL = 22.5 mg/kg, 90 mg/mL = 45 mg/kg, 180 mg/mL = 90 mg/kg, 360 mg/mL = 180 mg/kg. For mice, dosing volume = 2 mL/kg; 11.25 mg/mL = 22.5 mg/kg, 22.5 mg/mL = 45 mg/kg, 45 mg/mL = 90 mg/kg, 90 mg/mL = 180 mg/kg, 180 mg/mL = 360 mg/kg.

^b^ Animal room sample.

Table F-3 Results of Analyses of Dose Formulations Administered to Rats and Mice in the Three-month Dermal Studies of Sodium Thioglycolate

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration^a^ (mg/mL) | Difference from Target (%)
Rats
December 9, 2002 | December 12, 2002 | 22.5 | 21.5 | −4
| | 45 | 44.0 | −2
| | 90 | 85.1 | −5
| | 180 | 178.0 | −1
| | 360 | 363.0 | +1
| December 20 and 23, 2002^b^ | 22.5 | 15.94^c^ | −29
| | 45 | 36.4^c^ | −19
| | 90 | 84.7 | −6
| | 180 | 165.8 | −8
| | 360 | 254.7 | −29
January 27, 2003 | January 28, 2003 | 22.5 | 22.83^c^ | +1
| | 45 | 44.65 | −1
| | 90 | 82.63 | −8
| | 180 | 161.7 | −10
| | 360 | 345.6 | −4
| February 7, 2003^b^ | 22.5 | 10.02 | −55
| | 45 | 31.53 | −30
| | 90 | 64.03 | −29
| | 180 | 139.3 | −23
| | 360 | 258.2 | −28
March 11, 2003 | March 17, 2003 | 22.5 | 20.59 | −8
| | 45 | 43.4 | −4
| | 90 | 87.1 | −3
| | 180 | 175.8 | −2
| | 360 | 324.2 | −10
| March 24, 2003^b^ | 22.5 | 12.67 | −44
| | 45 | 34.8 | −23
| | 90 | 70.4 | −22
| | 180 | 129.8 | −28
| | 360 | 260.5 | −28
Mice
December 9, 2002 | December 12, 2002 | 11.25 | 10.78 | −4
| | 22.5 | 21.5 | −4
| | 45 | 44.0 | −2
| | 90 | 85.1 | −5
| | 180 | 178.0 | −1
| December 20 and 23, 2002^b^ | 11.25 | 9.31^c^ | −17
| | 22.5 | 21.14 | −6
| | 45 | 44.3 | −2
| | 90 | 90.3 | 0
| | 180 | 172.0 | −4
January 27, 2003 | January 28, 2003 | 11.25 | 12.06^c^ | +7
| | 22.5 | 22.83 | +1
| | 45 | 44.65 | −1
| | 90 | 82.63 | −8
| | 180 | 161.7 | −10
| February 7, 2003^b^ | 11.25 | 5.22 | −54
| | 22.5 | 13.38 | −41
| | 45 | 30.86 | −31
| | 90 | 63.62 | −29
| | 180 | 150.9 | −16
March 11, 2003 | March 17, 2003 | 11.25 | 10.45 | −7
| | 22.5 | 20.59 | −8
| | 45 | 43.4 | −4
| | 90 | 87.1 | −3
| | 180 | 175.8 | −2
| March 24, 2003^b^ | 11.25 | 3.12 | −72
| | 22.5 | 7.52 | −67
| | 45 | 23.4 | −48
| | 90 | 59.4 | −34
| | 180 | 135.3 | −25

^a^ Results of duplicate analyses. For rats, dosing volume = 0.5 mL/kg; 22.5 mg/mL = 11.25 mg/kg, 45 mg/mL = 22.5 mg/kg, 90 mg/mL = 45 mg/kg, 180 mg/mL = 90 mg/kg, 360 mg/mL = 180 mg/kg. For mice, dosing volume = 2 mL/kg; 11.25 mg/mL = 22.5 mg/kg, 22.5 mg/mL = 45 mg/kg, 45 mg/mL = 90 mg/kg, 90 mg/mL = 180 mg/kg, 180 mg/mL = 360 mg/kg.

^b^ Animal room samples.

^c^ Results of triplicate analyses.

Figure F-1

Infrared Absorption Spectrum of Sodium Thioglycolate

Figure F-2

Proton Nuclear Magnetic Resonance Spectrum of Sodium Thioglycolate

Figure F-3

Carbon-13 Nuclear Magnetic Resonance Spectrum of Sodium Thioglycolate