# Appendix E Reproductive Tissue Evaluations and Estrous Cycle Characterization

Table E-1 Summary of Reproductive Tissue Evaluations for Male Rats in the Three-month Dermal Study of Sodium Thioglycolate^a^

| Vehicle Control | 45 mg/kg | 90 mg/kg | 180 mg/kg
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 335 ± 4 | 339 ± 5 | 312 ± 9* | 319 ± 6*
L. Cauda epididymis | 0.1736 ± 0.0077 | 0.1761 ± 0.0048 | 0.1681 ± 0.0040 | 0.1746 ± 0.0038
L. Epididymis | 0.4638 ± 0.0094 | 0.4829 ± 0.0098 | 0.4601 ± 0.0093 | 0.4698 ± 0.0101
L. Testis | 1.5131 ± 0.0132 | 1.5008 ± 0.0252 | 1.4782 ± 0.0295 | 1.5296 ± 0.0283
Spermatid measurements
Spermatid heads (10^6^/testis) | 174.4 ± 6.3 | 177.0 ± 6.7 | 164.8 ± 5.3 | 179.6 ± 7.8
Spermatid heads (10^6^/g testis) | 125.4 ± 4.4 | 127.8 ± 4.1 | 122.2 ± 3.5 | 128.8 ± 4.2
Epididymal spermatozoal measurements
Sperm motility (%) | 81.80 ± 1.06 | 82.90 ± 0.86 | 82.22 ± 0.76^b^ | 83.50 ± 0.60
Sperm (10^6^/cauda epididymis) | 53.55 ± 9.53 | 58.00 ± 6.03 | 50.50 ± 9.69 | 50.55 ± 7.25
Sperm (10^6^/g cauda epididymis) | 323 ± 68 | 328 ± 33 | 298 ± 54 | 288 ± 38

* Significantly different (P ≤ 0.05) from the vehicle control group by Williams’ test.

^a^ Data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (tissue weights) or Dunn’s test (spermatid and epididymal spermatozoal measurements).

^b^ n = 9.

Table E-2 Estrous Cycle Characterization for Female Rats in the Three-month Dermal Study of Sodium Thioglycolate^a^

| Vehicle Control | 45 mg/kg | 90 mg/kg | 180 mg/kg
Number weighed at necropsy | 10 | 10 | 10 | 10
Necropsy body wt (g) | 177 ± 3 | 186 ± 3 | 180 ± 4 | 173 ± 4
Estrous cycle length (days) | 5.00 ± 0.00 | 4.75 ± 0.23 | 5.10 ± 0.10 | 4.90 ± 0.19
Estrous stages (% of cycle)
Diestrus | 58.3 | 63.3 | 53.3 | 63.3
Proestrus | 20.0 | 15.0 | 18.3 | 15.0
Estrus | 20.8 | 20.8 | 23.3 | 20.0
Metestrus | 0.8 | 0.8 | 5.0 | 1.7

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (body weight) or Dunn’s test (estrous cycle length). By multivariate analysis of variance, dosed females do not differ significantly from the vehicle control females in the relative length of time spent in the estrous stages.

Table E-3 Summary of Reproductive Tissue Evaluations for Male Mice in the Three-month Dermal Study of Sodium Thioglycolate^a^

| Vehicle Control | 90 mg/kg | 180 mg/kg | 360 mg/kg
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 29.0 ± 0.5 | 28.2 ± 0.6 | 28.8 ± 0.4 | 28.3 ± 0.3
L. Cauda epididymis | 0.0154 ± 0.0007 | 0.0158 ± 0.0005 | 0.0143 ± 0.0007 | 0.0167 ± 0.0008
L. Epididymis | 0.0472 ± 0.0021 | 0.0467 ± 0.0014 | 0.0479 ± 0.0021 | 0.0483 ± 0.0015
L. Testis | 0.1101 ± 0.0011 | 0.1120 ± 0.0017 | 0.1092 ± 0.0026 | 0.1079 ± 0.0030
Spermatid measurements
Spermatid heads (10^6^/testis) | 18.42 ± 0.74 | 19.43 ± 0.56 | 18.75 ± 1.01 | 18.03 ± 1.24
Spermatid heads (10^6^/g testis) | 175.2 ± 6.4 | 187.3 ± 4.3 | 184.9 ± 7.7 | 182.0 ± 9.0
Epididymal spermatozoal measurements
Sperm motility (%) | 83.89 ± 0.61^b^ | 84.50 ± 1.27 | 84.10 ± 0.87 | 84.00 ± 0.58
Sperm (10^6^/cauda epididymis) | 12.244 ± 1.630^b^ | 12.790 ± 1.519 | 9.340 ± 1.036 | 9.780 ± 0.797
Sperm (10^6^/g cauda epididymis) | 809 ± 115^b^ | 826 ± 115 | 680 ± 101 | 596 ± 52

^a^ Data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (body and tissue weights) or Dunn’s test (spermatid and epididymal spermatozoal measurements).

^b^ n = 9.

Table E-4 Estrous Cycle Characterization for Female Mice in the Three-month Dermal Study of Sodium Thioglycolate^a^

| Vehicle Control | 90 mg/kg | 180 mg/kg | 360 mg/kg
Number weighed at necropsy | 10 | 10 | 10 | 10
Necropsy body wt (g) | 24.4 ± 0.5 | 24.6 ± 0.5 | 25.3 ± 0.4 | 25.5 ± 0.4
Estrous cycle length (days) | 4.05 ± 0.05 | 3.95 ± 0.05 | 4.20 ± 0.11 | 4.10 ± 0.07
Estrous stages (% of cycle)
Diestrus | 24.2 | 26.7 | 26.7 | 25.8
Proestrus | 0.0 | 0.0 | 0.0 | 0.0
Estrus | 51.7 | 49.2 | 49.2 | 51.7
Metestrus | 24.2 | 24.2 | 24.2 | 22.5

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (body weight) or Dunn’s test (estrous cycle length). By multivariate analysis of variance, dosed females do not differ significantly from the vehicle control females in the relative length of time spent in the estrous stages.