# Appendix D Organ Weights and Organ-Weight-to-Body-Weight Ratios

Table D-1 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the Two-week Dermal Study of Sodium Thioglycolate^a^

| Vehicle Control | 11.25 mg/kg | 22.5 mg/kg | 45 mg/kg | 90 mg/kg | 180 mg/kg
n | 5 | 5 | 5 | 5 | 5 | 5
Male
Necropsy body wt | 151 ± 11 | 148 ± 4 | 162 ± 4 | 152 ± 5 | 164 ± 4 | 162 ± 6
Heart
Absolute | 0.607 ± 0.026 | 0.597 ± 0.013 | 0.640 ± 0.015 | 0.615 ± 0.023 | 0.649 ± 0.020 | 0.663 ± 0.026
Relative | 4.053 ± 0.142 | 4.031 ± 0.049 | 3.948 ± 0.103 | 4.053 ± 0.118 | 3.951 ± 0.105 | 4.098 ± 0.088
R. Kidney
Absolute | 0.719 ± 0.037 | 0.738 ± 0.025 | 0.811 ± 0.028 | 0.754 ± 0.037 | 0.823 ± 0.026* | 0.861 ± 0.033**
Relative | 4.790 ± 0.107 | 4.977 ± 0.072 | 4.994 ± 0.077 | 4.952 ± 0.111 | 5.003 ± 0.109 | 5.325 ± 0.118**
Liver
Absolute | 7.921 ± 0.632 | 8.080 ± 0.301 | 8.715 ± 0.299 | 7.817 ± 0.309 | 9.082 ± 0.363 | 9.525 ± 0.375*
Relative | 52.348 ± 1.267 | 54.567 ± 1.960 | 53.696 ± 1.035 | 51.460 ± 1.353 | 55.256 ± 1.972 | 58.881 ± 0.842*
Lung
Absolute | 1.801 ± 0.067 | 0.996 ± 0.031** | 1.054 ± 0.052** | 0.954 ± 0.056** | 0.991 ± 0.060** | 0.990 ± 0.061**
Relative | 12.220 ± 1.155 | 6.728 ± 0.205** | 6.511 ± 0.361** | 6.274 ± 0.285** | 6.011 ± 0.257** | 6.129 ± 0.347**
Spleen
Absolute | 0.443 ± 0.030 | 0.449 ± 0.015 | 0.474 ± 0.016 | 0.459 ± 0.020 | 0.497 ± 0.019 | 0.497 ± 0.019
Relative | 2.942 ± 0.092 | 3.031 ± 0.088 | 2.918 ± 0.035 | 3.015 ± 0.043 | 3.018 ± 0.072 | 3.077 ± 0.064
R. Testis
Absolute | 0.944 ± 0.061 | 0.891 ± 0.042 | 0.999 ± 0.026 | 0.933 ± 0.026 | 1.028 ± 0.035 | 0.949 ± 0.031
Relative | 6.262 ± 0.082 | 6.004 ± 0.203 | 6.162 ± 0.090 | 6.146 ± 0.084 | 6.249 ± 0.149 | 5.888 ± 0.228
Thymus
Absolute | 0.441 ± 0.033 | 0.424 ± 0.018 | 0.459 ± 0.019 | 0.433 ± 0.036 | 0.480 ± 0.035 | 0.475 ± 0.022
Relative | 2.916 ± 0.068 | 2.870 ± 0.155 | 2.825 ± 0.049 | 2.832 ± 0.155 | 2.921 ± 0.201 | 2.941 ± 0.131
Thyroid gland
Absolute | 0.018 ± 0.001 | 0.017 ± 0.001 | 0.017 ± 0.001 | 0.017 ± 0.001 | 0.019 ± 0.001 | 0.017 ± 0.001
Relative | 0.119 ± 0.011 | 0.112 ± 0.002 | 0.105 ± 0.003 | 0.114 ± 0.007 | 0.116 ± 0.006 | 0.105 ± 0.003
Female
Necropsy body wt | 128 ± 3 | 117 ± 6 | 115 ± 3 | 118 ± 5 | 120 ± 2 | 125 ± 2
Heart
Absolute | 0.531 ± 0.016 | 0.491 ± 0.020 | 0.468 ± 0.022 | 0.496 ± 0.020 | 0.485 ± 0.012 | 0.522 ± 0.013
Relative | 4.166 ± 0.086 | 4.189 ± 0.085 | 4.060 ± 0.123 | 4.204 ± 0.024 | 4.059 ± 0.122 | 4.171 ± 0.111
R. Kidney
Absolute | 0.664 ± 0.032 | 0.673 ± 0.038 | 0.638 ± 0.021 | 0.647 ± 0.015 | 0.704 ± 0.028 | 0.643 ± 0.018
Relative | 5.194 ± 0.151 | 5.725 ± 0.103 | 5.551 ± 0.209 | 5.501 ± 0.163 | 5.904 ± 0.298 | 5.139 ± 0.213
Liver
Absolute | 6.131 ± 0.265 | 5.442 ± 0.188 | 5.505 ± 0.139 | 5.789 ± 0.356 | 5.489 ± 0.064 | 5.921 ± 0.155
Relative | 47.987 ± 1.351 | 46.499 ± 0.967 | 47.843 ± 0.665 | 48.864 ± 1.009 | 45.911 ± 0.588 | 47.232 ± 0.777
Lung
Absolute | 0.914 ± 0.064 | 0.879 ± 0.041 | 0.887 ± 0.050 | 0.847 ± 0.029 | 0.841 ± 0.030 | 0.925 ± 0.046
Relative | 7.150 ± 0.430 | 7.513 ± 0.297 | 7.686 ± 0.269 | 7.187 ± 0.082 | 7.051 ± 0.329 | 7.384 ± 0.383
Spleen
Absolute | 0.407 ± 0.013 | 0.369 ± 0.012 | 0.346 ± 0.021* | 0.373 ± 0.019 | 0.386 ± 0.009 | 0.393 ± 0.008
Relative | 3.188 ± 0.064 | 3.170 ± 0.157 | 3.004 ± 0.151 | 3.154 ± 0.048 | 3.231 ± 0.081 | 3.138 ± 0.046
Thymus
Absolute | 0.370 ± 0.018 | 0.343 ± 0.030 | 0.308 ± 0.038 | 0.351 ± 0.030 | 0.363 ± 0.010 | 0.385 ± 0.011
Relative | 2.896 ± 0.101 | 2.915 ± 0.190 | 2.651 ± 0.271 | 2.958 ± 0.154 | 3.035 ± 0.076 | 3.075 ± 0.102
Thyroid gland
Absolute | 0.015 ± 0.000 | 0.015 ± 0.001 | 0.014 ± 0.001 | 0.014 ± 0.000 | 0.014 ± 0.001 | 0.014 ± 0.002
Relative | 0.116 ± 0.004 | 0.129 ± 0.003 | 0.118 ± 0.003 | 0.123 ± 0.005 | 0.114 ± 0.005 | 0.115 ± 0.012

* Significantly different (P ≤ 0.05) from the vehicle control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Table D-2 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the Three-month Dermal Study of Sodium Thioglycolate^a^

| Vehicle Control | 11.25 mg/kg | 22.5 mg/kg | 45 mg/kg | 90 mg/kg | 180 mg/kg
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 335 ± 4 | 334 ± 4 | 332 ± 7 | 339 ± 5 | 312 ± 9* | 319 ± 6*
Heart
Absolute | 0.973 ± 0.014 | 0.981 ± 0.022 | 0.955 ± 0.018 | 0.967 ± 0.010 | 0.950 ± 0.023 | 0.932 ± 0.019
Relative | 2.908 ± 0.031 | 2.939 ± 0.046 | 2.879 ± 0.036 | 2.851 ± 0.033 | 3.050 ± 0.050 | 2.920 ± 0.036
R. Kidney
Absolute | 1.139 ± 0.021 | 1.197 ± 0.026 | 1.166 ± 0.024 | 1.179 ± 0.019 | 1.139 ± 0.023 | 1.173 ± 0.024
Relative | 3.404 ± 0.044 | 3.589 ± 0.064 | 3.516 ± 0.054 | 3.477 ± 0.054 | 3.658 ± 0.042** | 3.676 ± 0.048**
Liver
Absolute | 11.22 ± 0.27 | 11.90 ± 0.26 | 11.71 ± 0.34 | 12.36 ± 0.29* | 10.46 ± 0.35 | 11.26 ± 0.26
Relative | 33.523 ± 0.478 | 35.665 ± 0.616 | 35.243 ± 0.619 | 36.383 ± 0.461** | 33.531 ± 0.738 | 35.295 ± 0.664
Lung
Absolute | 1.532 ± 0.063 | 1.502 ± 0.051 | 1.541 ± 0.085 | 1.518 ± 0.053 | 1.451 ± 0.045 | 1.497 ± 0.027
Relative | 4.580 ± 0.185 | 4.500 ± 0.140 | 4.627 ± 0.192 | 4.477 ± 0.156 | 4.659 ± 0.124 | 4.694 ± 0.081
Spleen
Absolute | 0.717 ± 0.010 | 0.717 ± 0.012 | 0.719 ± 0.017 | 0.721 ± 0.016 | 0.705 ± 0.016 | 0.722 ± 0.016
Relative | 2.144 ± 0.022 | 2.149 ± 0.029 | 2.167 ± 0.042 | 2.123 ± 0.028 | 2.266 ± 0.040* | 2.262 ± 0.031*
R. Testis
Absolute | 1.442 ± 0.025 | 1.468 ± 0.023 | 1.386 ± 0.025 | 1.419 ± 0.029 | 1.435 ± 0.030 | 1.482 ± 0.028
Relative | 4.315 ± 0.089 | 4.399 ± 0.042 | 4.182 ± 0.075 | 4.181 ± 0.066 | 4.614 ± 0.082** | 4.649 ± 0.082**
Thymus
Absolute | 0.301 ± 0.009 | 0.315 ± 0.016 | 0.307 ± 0.031 | 0.349 ± 0.026 | 0.296 ± 0.009 | 0.317 ± 0.013
Relative | 0.899 ± 0.022 | 0.941 ± 0.043 | 0.916 ± 0.088 | 1.026 ± 0.066 | 0.959 ± 0.050 | 0.993 ± 0.042
Thyroid gland
Absolute | 0.026 ± 0.001 | 0.026 ± 0.001 | 0.027 ± 0.001 | 0.030 ± 0.005 | 0.028 ± 0.002 | 0.027 ± 0.001
Relative | 0.078 ± 0.004 | 0.077 ± 0.003 | 0.082 ± 0.004 | 0.088 ± 0.014 | 0.092 ± 0.006 | 0.084 ± 0.004
Female
Necropsy body wt | 177 ± 3 | 185 ± 3 | 185 ± 3 | 186 ± 3 | 180 ± 4 | 173 ± 4
Heart
Absolute | 0.652 ± 0.013 | 0.646 ± 0.016 | 0.658 ± 0.008 | 0.647 ± 0.011 | 0.666 ± 0.016 | 0.643 ± 0.017
Relative | 3.679 ± 0.040 | 3.478 ± 0.047 | 3.575 ± 0.066 | 3.482 ± 0.045 | 3.709 ± 0.081 | 3.711 ± 0.060
R. Kidney
Absolute | 0.695 ± 0.014 | 0.726 ± 0.009 | 0.716 ± 0.010 | 0.723 ± 0.020 | 0.746 ± 0.021 | 0.724 ± 0.017
Relative | 3.922 ± 0.041 | 3.914 ± 0.025 | 3.884 ± 0.045 | 3.889 ± 0.087 | 4.147 ± 0.090* | 4.181 ± 0.069**
Liver
Absolute | 5.602 ± 0.173 | 5.587 ± 0.123 | 6.036 ± 0.156 | 5.896 ± 0.153 | 5.945 ± 0.141 | 5.659 ± 0.127
Relative | 31.564 ± 0.680 | 30.129 ± 0.484 | 32.693 ± 0.571 | 31.674 ± 0.481 | 33.084 ± 0.659 | 32.707 ± 0.689
Lung
Absolute | 1.053 ± 0.029 | 1.001 ± 0.043 | 0.978 ± 0.022 | 1.101 ± 0.047 | 1.059 ± 0.041 | 1.070 ± 0.090
Relative | 5.930 ± 0.083 | 5.394 ± 0.197 | 5.302 ± 0.104 | 5.932 ± 0.266 | 5.882 ± 0.179 | 6.167 ± 0.491
Spleen
Absolute | 0.441 ± 0.007 | 0.448 ± 0.009 | 0.444 ± 0.006 | 0.451 ± 0.012 | 0.442 ± 0.012 | 0.432 ± 0.013
Relative | 2.488 ± 0.023 | 2.416 ± 0.044 | 2.409 ± 0.035 | 2.423 ± 0.048 | 2.460 ± 0.066 | 2.488 ± 0.040
Thymus
Absolute | 0.259 ± 0.032 | 0.254 ± 0.006 | 0.231 ± 0.007 | 0.233 ± 0.007 | 0.230 ± 0.007 | 0.230 ± 0.011
Relative | 1.474 ± 0.208 | 1.370 ± 0.028 | 1.252 ± 0.041 | 1.253 ± 0.040 | 1.282 ± 0.045 | 1.333 ± 0.067
Thyroid gland
Absolute | 0.026 ± 0.001 | 0.026 ± 0.001 | 0.023 ± 0.001 | 0.024 ± 0.001 | 0.026 ± 0.001^b^ | 0.023 ± 0.001^b^
Relative | 0.145 ± 0.005 | 0.141 ± 0.006 | 0.123 ± 0.004* | 0.130 ± 0.007 | 0.140 ± 0.006^b^ | 0.133 ± 0.003^b^

* Significantly different (P ≤ 0.05) from the vehicle control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

^b^ n = 9.

Table D-3 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Two-week Dermal Study of Sodium Thioglycolate^a^

| Vehicle Control | 22.5 mg/kg | 45 mg/kg | 90 mg/kg | 180 mg/kg | 360 mg/kg
Male
n | 5 | 5 | 5 | 5 | 5 | 5
Necropsy body wt | 23.6 ± 0.5 | 23.5 ± 0.3 | 24.7 ± 0.9 | 23.9 ± 0.3 | 25.1 ± 0.4 | 24.7 ± 0.4
Heart
Absolute | 0.144 ± 0.004 | 0.137 ± 0.006 | 0.140 ± 0.007 | 0.137 ± 0.003 | 0.146 ± 0.002 | 0.145 ± 0.006
Relative | 6.080 ± 0.082 | 5.809 ± 0.197 | 5.634 ± 0.106 | 5.749 ± 0.100 | 5.825 ± 0.166 | 5.874 ± 0.178
R. Kidney
Absolute | 0.313 ± 0.014 | 0.262 ± 0.012 | 0.297 ± 0.022 | 0.279 ± 0.006 | 0.309 ± 0.015 | 0.326 ± 0.025
Relative | 13.232 ± 0.457 | 11.136 ± 0.460 | 11.932 ± 0.496 | 11.704 ± 0.247 | 12.299 ± 0.556 | 13.178 ± 0.910
Liver
Absolute | 1.486 ± 0.067 | 1.456 ± 0.029 | 1.525 ± 0.059 | 1.446 ± 0.034 | 1.570 ± 0.032 | 1.533 ± 0.062
Relative | 62.757 ± 1.864 | 61.957 ± 0.667 | 61.686 ± 1.239 | 60.588 ± 1.068 | 62.475 ± 0.989 | 61.981 ± 1.697
Lung
Absolute | 0.210 ± 0.018 | 0.215 ± 0.014 | 0.210 ± 0.014 | 0.198 ± 0.013 | 0.214 ± 0.004 | 0.187 ± 0.016
Relative | 8.875 ± 0.733 | 9.149 ± 0.579 | 8.447 ± 0.284 | 8.296 ± 0.515 | 8.532 ± 0.310 | 7.574 ± 0.626
Spleen
Absolute | 0.077 ± 0.004 | 0.071 ± 0.003 | 0.082 ± 0.007 | 0.075 ± 0.002 | 0.079 ± 0.003 | 0.077 ± 0.004
Relative | 3.244 ± 0.113 | 3.005 ± 0.112 | 3.294 ± 0.203 | 3.141 ± 0.123 | 3.147 ± 0.075 | 3.103 ± 0.133
R. Testis
Absolute | 0.108 ± 0.003 | 0.105 ± 0.003 | 0.108 ± 0.006 | 0.102 ± 0.003 | 0.108 ± 0.001 | 0.105 ± 0.005
Relative | 4.554 ± 0.136 | 4.454 ± 0.142 | 4.354 ± 0.132 | 4.286 ± 0.139 | 4.309 ± 0.082 | 4.250 ± 0.158
Thymus
Absolute | 0.055 ± 0.007 | 0.050 ± 0.005 | 0.055 ± 0.003 | 0.053 ± 0.005 | 0.053 ± 0.003 | 0.053 ± 0.005
Relative | 2.293 ± 0.257 | 2.109 ± 0.202 | 2.228 ± 0.106 | 2.242 ± 0.237 | 2.114 ± 0.108 | 2.138 ± 0.164
Thyroid gland
Absolute | 0.004 ± 0.001 | 0.005 ± 0.001 | 0.004 ± 0.000 | 0.004 ± 0.000 | 0.003 ± 0.000 | 0.004 ± 0.001
Relative | 0.152 ± 0.031 | 0.203 ± 0.033 | 0.163 ± 0.016 | 0.176 ± 0.008 | 0.119 ± 0.012 | 0.147 ± 0.022
Female
n | 5 | 5 | 5 | 5 | 5 | 4
Necropsy body wt | 21.3 ± 0.2 | 21.2 ± 0.3 | 21.5 ± 0.2 | 21.8 ± 0.3 | 22.1 ± 0.5 | 22.2 ± 0.6
Heart
Absolute | 0.132 ± 0.003 | 0.134 ± 0.005 | 0.135 ± 0.004 | 0.132 ± 0.005 | 0.133 ± 0.004 | 0.128 ± 0.008
Relative | 6.201 ± 0.153 | 6.350 ± 0.201 | 6.273 ± 0.161 | 6.062 ± 0.218 | 5.998 ± 0.097 | 5.755 ± 0.255
R. Kidney
Absolute | 0.224 ± 0.012 | 0.228 ± 0.020 | 0.220 ± 0.010 | 0.223 ± 0.011 | 0.233 ± 0.014 | 0.231 ± 0.027
Relative | 10.535 ± 0.577 | 10.766 ± 0.935 | 10.231 ± 0.506 | 10.256 ± 0.497 | 10.519 ± 0.622 | 10.362 ± 1.090
Liver
Absolute | 1.395 ± 0.045 | 1.393 ± 0.051 | 1.347 ± 0.038 | 1.337 ± 0.059 | 1.442 ± 0.052 | 1.401 ± 0.072
Relative | 65.552 ± 1.577 | 65.803 ± 1.838 | 62.537 ± 1.772 | 61.277 ± 1.895 | 65.060 ± 1.094 | 62.973 ± 1.718
Lung
Absolute | 0.199 ± 0.012 | 0.206 ± 0.013 | 0.202 ± 0.006 | 0.187 ± 0.009 | 0.196 ± 0.014 | 0.196 ± 0.013
Relative | 9.368 ± 0.612 | 9.743 ± 0.593 | 9.402 ± 0.330 | 8.625 ± 0.478 | 8.843 ± 0.513 | 8.798 ± 0.461
Spleen
Absolute | 0.103 ± 0.008 | 0.097 ± 0.003 | 0.102 ± 0.004 | 0.097 ± 0.004 | 0.099 ± 0.005 | 0.092 ± 0.006
Relative | 4.827 ± 0.380 | 4.571 ± 0.158 | 4.749 ± 0.190 | 4.447 ± 0.117 | 4.475 ± 0.186 | 4.132 ± 0.256
Thymus
Absolute | 0.076 ± 0.003 | 0.091 ± 0.004 | 0.079 ± 0.006 | 0.072 ± 0.003 | 0.079 ± 0.005 | 0.083 ± 0.008
Relative | 3.552 ± 0.129 | 4.296 ± 0.196 | 3.679 ± 0.279 | 3.296 ± 0.138 | 3.556 ± 0.256 | 3.726 ± 0.303
Thyroid gland
Absolute | 0.003 ± 0.000 | 0.004 ± 0.000 | 0.005 ± 0.000* | 0.003 ± 0.000 | 0.005 ± 0.000 | 0.003 ± 0.000
Relative | 0.151 ± 0.018 | 0.179 ± 0.022 | 0.222 ± 0.016* | 0.157 ± 0.013 | 0.208 ± 0.019 | 0.147 ± 0.023

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunnett’s test.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Table D-4 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Three-month Dermal Study of Sodium Thioglycolate^a^

| Vehicle Control | 22.5 mg/kg | 45 mg/kg | 90 mg/kg | 180 mg/kg | 360 mg/kg
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 29.0 ± 0.5 | 28.2 ± 0.3 | 28.1 ± 0.7 | 28.2 ± 0.6 | 28.8 ± 0.4 | 28.3 ± 0.3
Heart
Absolute | 0.137 ± 0.002 | 0.147 ± 0.002 | 0.147 ± 0.004 | 0.141 ± 0.002 | 0.148 ± 0.002* | 0.148 ± 0.002*
Relative | 4.725 ± 0.041 | 5.196 ± 0.087** | 5.213 ± 0.087** | 5.018 ± 0.110** | 5.141 ± 0.067** | 5.247 ± 0.080**
R. Kidney
Absolute | 0.282 ± 0.009 | 0.280 ± 0.007 | 0.266 ± 0.007 | 0.283 ± 0.009 | 0.287 ± 0.007 | 0.296 ± 0.008
Relative | 9.714 ± 0.178 | 9.918 ± 0.173 | 9.450 ± 0.120 | 10.041 ± 0.227 | 9.942 ± 0.143 | 10.449 ± 0.216*
Liver
Absolute | 1.300 ± 0.022 | 1.281 ± 0.028 | 1.251 ± 0.023 | 1.329 ± 0.035 | 1.404 ± 0.025** | 1.409 ± 0.025**
Relative | 44.876 ± 0.512 | 45.361 ± 0.801 | 44.580 ± 0.621 | 47.151 ± 0.851* | 48.771 ± 0.692** | 49.844 ± 0.696**
Lung
Absolute | 0.205 ± 0.007 | 0.212 ± 0.011 | 0.202 ± 0.006 | 0.220 ± 0.012 | 0.214 ± 0.011 | 0.224 ± 0.017
Relative | 7.103 ± 0.296 | 7.494 ± 0.342 | 7.210 ± 0.287 | 7.824 ± 0.415 | 7.397 ± 0.306 | 7.917 ± 0.588
Spleen
Absolute | 0.059 ± 0.002 | 0.052 ± 0.001 | 0.054 ± 0.001 | 0.059 ± 0.002 | 0.061 ± 0.001 | 0.063 ± 0.002
Relative | 2.046 ± 0.056 | 1.824 ± 0.043 | 1.940 ± 0.064 | 2.108 ± 0.060 | 2.118 ± 0.026 | 2.230 ± 0.070*
R. Testis
Absolute | 0.118 ± 0.002 | 0.120 ± 0.002 | 0.124 ± 0.002 | 0.117 ± 0.001 | 0.119 ± 0.002 | 0.115 ± 0.003
Relative | 4.079 ± 0.073 | 4.240 ± 0.085 | 4.423 ± 0.147 | 4.146 ± 0.074 | 4.145 ± 0.086 | 4.066 ± 0.091
Thymus
Absolute | 0.040 ± 0.005 | 0.035 ± 0.002 | 0.041 ± 0.003 | 0.038 ± 0.003 | 0.047 ± 0.005 | 0.040 ± 0.003
Relative | 1.402 ± 0.165 | 1.244 ± 0.076 | 1.455 ± 0.129 | 1.362 ± 0.098 | 1.654 ± 0.182 | 1.400 ± 0.117
Thyroid gland
Absolute | 0.005 ± 0.001 | 0.005 ± 0.000 | 0.005 ± 0.001 | 0.006 ± 0.000 | 0.005 ± 0.000 | 0.006 ± 0.001
Relative | 0.175 ± 0.021 | 0.166 ± 0.015 | 0.182 ± 0.022 | 0.197 ± 0.015 | 0.187 ± 0.009 | 0.196 ± 0.019
Female
Necropsy body wt | 24.4 ± 0.5 | 24.8 ± 0.4 | 25.4 ± 0.7 | 24.6 ± 0.5 | 25.3 ± 0.4 | 25.5 ± 0.4
Heart
Absolute | 0.124 ± 0.003 | 0.131 ± 0.003 | 0.134 ± 0.002* | 0.129 ± 0.002* | 0.134 ± 0.003** | 0.140 ± 0.003**
Relative | 5.074 ± 0.097 | 5.278 ± 0.094 | 5.300 ± 0.117 | 5.257 ± 0.104 | 5.307 ± 0.135 | 5.481 ± 0.109*
R. Kidney
Absolute | 0.179 ± 0.006 | 0.189 ± 0.005 | 0.191 ± 0.004 | 0.184 ± 0.004 | 0.196 ± 0.003* | 0.198 ± 0.002*
Relative | 7.350 ± 0.166 | 7.610 ± 0.180 | 7.531 ± 0.201 | 7.482 ± 0.133 | 7.743 ± 0.089 | 7.755 ± 0.111
Liver
Absolute | 1.118 ± 0.030 | 1.197 ± 0.029* | 1.256 ± 0.025** | 1.233 ± 0.033** | 1.285 ± 0.019** | 1.337 ± 0.027**
Relative | 45.867 ± 0.844 | 48.279 ± 0.873 | 49.544 ± 1.129** | 50.063 ± 0.924** | 50.930 ± 0.677** | 52.404 ± 0.821**
Lung
Absolute | 0.225 ± 0.015 | 0.225 ± 0.017 | 0.193 ± 0.009 | 0.230 ± 0.013 | 0.238 ± 0.017 | 0.211 ± 0.008
Relative | 9.200 ± 0.497 | 9.100 ± 0.715 | 7.627 ± 0.424 | 9.332 ± 0.518 | 9.469 ± 0.725 | 8.260 ± 0.323
Spleen
Absolute | 0.073 ± 0.003 | 0.082 ± 0.003 | 0.084 ± 0.003* | 0.080 ± 0.002 | 0.081 ± 0.003 | 0.085 ± 0.004*
Relative | 2.986 ± 0.091 | 3.317 ± 0.139 | 3.305 ± 0.080 | 3.243 ± 0.091 | 3.214 ± 0.135 | 3.315 ± 0.142
Thymus
Absolute | 0.050 ± 0.002 | 0.049 ± 0.002 | 0.049 ± 0.003 | 0.046 ± 0.003 | 0.047 ± 0.002 | 0.047 ± 0.003
Relative | 2.035 ± 0.077 | 2.002 ± 0.091 | 1.926 ± 0.121 | 1.869 ± 0.094 | 1.871 ± 0.061 | 1.840 ± 0.096
Thyroid gland
Absolute | 0.006 ± 0.000 | 0.005 ± 0.000 | 0.005 ± 0.000 | 0.006 ± 0.000 | 0.006 ± 0.000 | 0.006 ± 0.000
Relative | 0.239 ± 0.011 | 0.214 ± 0.013 | 0.200 ± 0.018 | 0.233 ± 0.018 | 0.230 ± 0.010 | 0.247 ± 0.012

* Significantly different (P ≤ 0.05) from the vehicle control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).