# Appendix C Clinical Pathology Results

Table C-1 Hematology and Clinical Chemistry Data for Rats in the Three-month Dermal Study of Sodium Thioglycolate^a^

| Vehicle Control | 11.25 mg/kg | 22.5 mg/kg | 45 mg/kg | 90 mg/kg | 180 mg/kg
Male
Hematology
n
Day 4 | 8 | 9 | 9 | 9 | 9 | 8
Day 22 | 9 | 10 | 10 | 10 | 10 | 10
Week 14 | 10 | 10 | 10 | 10 | 10 | 10
Hematocrit (%)
Day 4 | 40.3 ± 0.7 | 40.8 ± 0.5 | 39.7 ± 0.4 | 39.7 ± 0.6 | 39.1 ± 0.7 | 41.0 ± 0.8
Day 22 | 45.6 ± 1.2 | 43.9 ± 0.5 | 44.1 ± 0.9 | 44.2 ± 0.4 | 44.6 ± 0.6 | 43.8 ± 0.6
Week 14 | 45.3 ± 0.3 | 45.1 ± 0.6 | 45.8 ± 0.6 | 44.6 ± 0.6 | 46.1 ± 0.4 | 45.4 ± 0.4
Hemoglobin (g/dL)
Day 4 | 13.4 ± 0.2 | 13.5 ± 0.2 | 13.2 ± 0.1 | 13.2 ± 0.2 | 13.0 ± 0.2 | 13.6 ± 0.3
Day 22 | 15.2 ± 0.4 | 14.6 ± 0.2 | 14.7 ± 0.3 | 14.7 ± 0.1 | 14.9 ± 0.2 | 14.6 ± 0.2
Week 14 | 15.7 ± 0.1 | 15.6 ± 0.2 | 15.8 ± 0.2 | 15.5 ± 0.2 | 15.9 ± 0.2 | 15.8 ± 0.2
Erythrocytes (10^6^/μL)
Day 4 | 6.79 ± 0.12 | 6.87 ± 0.10 | 6.70 ± 0.06 | 6.75 ± 0.09 | 6.62 ± 0.13 | 6.90 ± 0.13
Day 22 | 7.71 ± 0.21 | 7.42 ± 0.09 | 7.45 ± 0.15 | 7.45 ± 0.08 | 7.54 ± 0.11 | 7.38 ± 0.10
Week 14 | 9.13 ± 0.06 | 9.10 ± 0.11 | 9.19 ± 0.12 | 9.04 ± 0.11 | 9.26 ± 0.08 | 9.15 ± 0.08
Reticulocytes (10^6^/μL)
Day 4 | 0.47 ± 0.02^b^ | 0.54 ± 0.02 | 0.53 ± 0.03 | 0.53 ± 0.02 | 0.45 ± 0.03 | 0.53 ± 0.02
Day 22 | 0.30 ± 0.03 | 0.31 ± 0.02 | 0.28 ± 0.02 | 0.32 ± 0.01 | 0.30 ± 0.01 | 0.30 ± 0.02
Week 14 | 0.20 ± 0.01 | 0.22 ± 0.02 | 0.22 ± 0.01 | 0.21 ± 0.01 | 0.23 ± 0.01 | 0.21 ± 0.01
Mean cell volume (fL)
Day 4 | 59.3 ± 0.3 | 59.4 ± 0.3 | 59.2 ± 0.3 | 58.8 ± 0.2 | 59.1 ± 0.2 | 59.4 ± 0.2
Day 22 | 59.1 ± 0.2 | 59.2 ± 0.2 | 58.9 ± 0.2 | 59.3 ± 0.2 | 59.3 ± 0.2 | 59.3 ± 0.2
Week 14 | 49.7 ± 0.2 | 49.4 ± 0.2 | 49.9 ± 0.2 | 49.3 ± 0.2 | 50.0 ± 0.2 | 49.7 ± 0.2
Mean cell hemoglobin (pg)
Day 4 | 19.7 ± 0.1 | 19.7 ± 0.1 | 19.6 ± 0.1 | 19.6 ± 0.1 | 19.6 ± 0.1 | 19.7 ± 0.1
Day 22 | 19.7 ± 0.1 | 19.7 ± 0.1 | 19.7 ± 0.1 | 19.8 ± 0.1 | 19.7 ± 0.1 | 19.8 ± 0.1
Week 14 | 17.2 ± 0.1 | 17.2 ± 0.1 | 17.3 ± 0.1 | 17.1 ± 0.1 | 17.2 ± 0.1 | 17.2 ± 0.1
Mean cell hemoglobin concentration (g/dL)
Day 4 | 33.3 ± 0.0 | 33.2 ± 0.1 | 33.2 ± 0.1 | 33.2 ± 0.1 | 33.3 ± 0.1 | 33.2 ± 0.1
Day 22 | 33.3 ± 0.1 | 33.3 ± 0.1 | 33.4 ± 0.1 | 33.4 ± 0.1 | 33.4 ± 0.1 | 33.3 ± 0.1
Week 14 | 34.5 ± 0.1 | 34.6 ± 0.1 | 34.6 ± 0.1 | 34.6 ± 0.1 | 34.5 ± 0.1 | 34.7 ± 0.1
Platelets (10^3^/μL)
Day 4 | 594.4 ± 26.7 | 560.0 ± 39.8 | 530.6 ± 25.5 | 591.0 ± 15.2 | 561.8 ± 30.2 | 569.5 ± 29.0
Day 22 | 522.4 ± 36.5 | 563.7 ± 18.5 | 534.1 ± 31.0 | 512.3 ± 20.3 | 545.3 ± 14.1 | 519.0 ± 17.5
Week 14 | 511.6 ± 13.1 | 503.6 ± 12.8 | 518.3 ± 13.9 | 525.5 ± 12.2 | 524.8 ± 15.9 | 502.9 ± 13.8
Leukocytes (10^3^/μL)
Day 4 | 10.61 ± 0.63 | 9.27 ± 0.52 | 10.13 ± 0.43 | 9.47 ± 0.43 | 10.33 ± 0.67 | 10.79 ± 0.50
Week 14 | 10.91 ± 0.39 | 11.08 ± 0.38 | 10.60 ± 0.45 | 10.99 ± 0.51 | 10.77 ± 0.38 | 9.75 ± 0.41
Segmented neutrophils (10^3^/μL)
Day 4 | 1.18 ± 0.07 | 1.03 ± 0.08 | 1.17 ± 0.08 | 1.05 ± 0.05 | 1.13 ± 0.07 | 1.33 ± 0.19
Week 14 | 2.88 ± 0.18 | 3.03 ± 0.21 | 2.57 ± 0.22 | 2.76 ± 0.14 | 2.98 ± 0.14 | 2.19 ± 0.19
Lymphocytes (10^3^/μL)
Day 4 | 8.55 ± 0.51 | 7.44 ± 0.39 | 8.01 ± 0.42 | 7.68 ± 0.33 | 8.33 ± 0.54 | 8.56 ± 0.42
Week 14 | 7.09 ± 0.27 | 6.87 ± 0.34 | 7.08 ± 0.32 | 7.20 ± 0.39 | 6.78 ± 0.27 | 6.77 ± 0.33
Monocytes (10^3^/μL)
Day 4 | 0.65 ± 0.06 | 0.58 ± 0.05 | 0.61 ± 0.04 | 0.55 ±0.06 | 0.62 ± 0.06 | 0.69 ± 0.03
Week 14 | 0.59 ± 0.05 | 0.74 ± 0.06 | 0.60 ± 0.05 | 0.61 ± 0.06 | 0.61 ± 0.06 | 0.47 ± 0.03
Basophils (10^3^/μL)
Day 4 | 0.228 ± 0.027 | 0.189 ± 0.018 | 0.289 ± 0.065 | 0.183 ± 0.021 | 0.224 ± 0.031 | 0.20 ± 0.023
Week 14 | 0.228 ± 0.026 | 0.288 ± 0.018 | 0.222 ± 0.022 | 0.295 ± 0.067 | 0.259 ± 0.032 | 0.209 ± 0.025
Eosinophils (10^3^/μL)
Day 4 | 0.03 ± 0.00 | 0.02 ± 0.00 | 0.05 ± 0.02 | 0.03 ± 0.00 | 0.03 ± 0.01 | 0.03 ±0.00
Week 14 | 0.12 ± 0.01 | 0.15 ± 0.01 | 0.12 ± 0.01 | 0.14 ± 0.02 | 0.13 ± 0.02 | 0.10 ± 0.01
Clinical Chemistry
n
Day 4 | 10 | 10 | 9 | 10 | 10 | 10
Day 22 | 10 | 10 | 10 | 10 | 10 | 10
Week 14 | 10 | 10 | 10 | 10 | 9 | 10
Urea nitrogen (mg/dL)
Day 4 | 14.5 ± 0.7 | 5.8 ± 0.8 | 15.1 ± 0.6 | 14.3 ± 0.5 | 14.3 ± 0.4 | 15.5 ± 0.8
Day 22 | 16.9 ± 0.6 | 19.2 ± 0.5* | 17.8 ± 0.4 | 19.4 ± 0.9* | 17.8 ± 0.6 | 18.2 ± 0.4
Week 14 | 17.6 ± 1.0 | 17.8 ± 0.8 | 18.0 ± 1.1 | 18.7 ± 0.7 | 18.2 ± 0.8 | 19.9 ± 0.5**
Creatinine (mg/dL)
Day 4 | 0.27 ± 0.02 | 0.29 ± 0.01 | 0.29 ± 0.01 | 0.28 ± 0.01 | 0.28 ± 0.01 | 0.28 ± 0.01
Day 22 | 0.32 ± 0.01 | 0.37 ± 0.02 | 0.32 ± 0.01 | 0.31 ± 0.01 | 0.32 ± 0.01 | 0.31 ± 0.01
Week 14 | 0.40 ± 0.02 | 0.39 ± 0.01 | 0.41 ± 0.01 | 0.41 ± 0.01 | 0.41 ± 0.01 | 0.42 ± 0.01
Total protein (g/dL)
Day 4 | 5.9 ± 0.1 | 5.9 ± 0.1 | 5.8 ± 0.1 | 5.8 ± 0.1 | 5.9 ± 0.1 | 5.9 ± 0.1
Day 22 | 6.4 ± 0.1 | 6.4 ± 0.1 | 6.2 ± 0.1 | 6.4 ± 0.1 | 6.4 ± 0.1 | 6.3 ± 0.1
Week 14 | 7.0 ± 0.1 | 7.2 ± 0.1 | 7.3 ± 0.1 | 7.3 ± 0.1 | 7.1 ± 0.1 | 7.3 ± 0.1*
Albumin (g/dL)
Day 4 | 4.0 ± 0.0 | 4.1 ± 0.0 | 4.0 ± 0.1 | 4.0 ± 0.1 | 4.0 ± 0.0 | 4.0 ± 0.1
Day 22 | 4.3 ± 0.1 | 4.3 ± 0.0 | 4.2 ± 0.0 | 4.3 ± 0.0 | 4.3 ± 0.0 | 4.2 ± 0.0
Week 14 | 4.5 ± 0.0 | 4.6 ± 0.0 | 4.7 ± 0.0* | 4.6 ± 0.0 | 4.6 ± 0.0 | 4.7 ± 0.0*
Globulin (g/dL)
Day 4 | 1.9 ± 0.0 | 1.9 ± 0.0 | 1.8 ± 0.0 | 1.8 ± 0.0 | 1.9 ± 0.1 | 1.8 ± 0.0
Day 22 | 2.1 ± 0.0 | 2.1 ± 0.1 | 2.0 ± 0.1 | 2.1 ± 0.0 | 2.1 ± 0.1 | 2.0 ± 0.0
Week 14 | 2.5 ± 0.1 | 2.6 ± 0.1 | 2.7 ± 0.1 | 2.7 ± 0.0 | 2.6 ± 0.0 | 2.7 ± 0.0
Albumin/globulin ratio
Day 4 | 2.1 ± 0.0 | 2.2 ± 0.0 | 2.2 ± 0.0 | 2.2 ± 0.0 | 2.2 ± 0.0 | 2.2 ± 0.0
Day 22 | 2.0 ± 0.0 | 2.1 ± 0.0 | 2.1 ± 0.1 | 2.1 ± 0.0 | 2.1 ± 0.1 | 2.1 ± 0.0
Week 14 | 1.8 ± 0.0 | 1.8 ± 0.0 | 1.8 ± 0.0 | 1.7 ± 0.0 | 1.8 ± 0.0 | 1.7 ± 0.0
Cholesterol (mg/dL)
Day 4 | 114 ± 4 | 113 ± 3 | 112 ± 4 | 113 ± 3 | 110 ± 3 | 107 ± 4
Day 22 | 98 ± 3 | 101 ± 3 | 97 ± 3 | 101 ± 3 | 100 ± 2 | 95 ± 3
Week 14 | 100 ± 2 | 105 ± 2 | 106 ± 2 | 107 ± 2 | 95 ± 2 | 106 ± 2
Alanine aminotransferase (IU/L)
Day 4 | 68 ± 2 | 66 ± 1 | 66 ± 2 | 65 ± 1 | 64 ± 2 | 66 ± 1
Day 22 | 64 ± 2 | 62 ± 2 | 60 ± 1 | 64 ± 1 | 63 ± 2 | 63 ± 2
Week 14 | 64 ± 3 | 74 ± 5 | 74 ± 5 | 76 ± 4 | 73 ± 5 | 76 ± 3
Alkaline phosphatase (IU/L)
Day 4 | 839 ± 22 | 841 ± 13 | 838 ± 24 | 824 ± 18 | 822 ± 13 | 808 ± 28
Day 22 | 598 ± 23 | 605 ± 14 | 590 ± 14 | 603 ± 9 | 611 ± 9 | 593 ± 17
Week 14 | 216 ± 6 | 222 ± 7 | 235 ± 7 | 237 ± 3 | 223 ± 7 | 227 ± 5
Creatine kinase (IU/L)
Day 4 | 306 ± 52 | 286 ± 25 | 515 ± 110 | 488 ± 169 | 381 ± 61 | 344 ± 65
Day 22 | 253 ± 38^c^ | 210 ± 14 | 230 ± 21 | 220 ± 24 | 190 ± 18 | 285 ± 26
Week 14 | 173 ± 32 | 301 ± 49 | 192 ± 29 | 217 ± 25 | 235 ± 49 | 233 ± 31
Sorbitol dehydrogenase (IU/L)
Day 4 | 11 ± 1 | 13 ± 1 | 12 ± 1^d^ | 11 ± 1 | 13 ± 1 | 13 ± 1
Day 22 | 14 ± 1 | 18 ± 1 | 17 ± 1 | 15 ± 1 | 15 ± 1 | 17 ± 1
Week 14 | 12 ± 1 | 12 ± 1 | 15 ± 1 | 16 ± 1 | 13 ± 1 | 16 ± 1
Bile acids (µmol/L)
Day 4 | 35.2 ± 4.5 | 31.3 ± 3.6 | 34.6 ± 2.4^d^ | 34.0 ± 4.1 | 31.8 ± 2.5 | 40.6 ± 2.8
Day 22 | 34.7 ± 4.0 | 39.7 ± 2.9 | 30.2 ± 2.7 | 38.3 ± 5.6 | 34.3 ± 2.2 | 36.8 ± 3.8
Week 14 | 45.4 ± 3.5 | 46.7 ± 6.7 | 50.8 ± 4.4 | 45.8 ± 3.8 | 47.1 ± 5.0 | 50.1 ± 4.2
3-Hydroxybutyrate (µmol/L)
Day 4 | 106.6 ± 12.5 | 109.0 ± 11.4 | 121.1 ± 11.1^d^ | 148.1 ± 15.3 | 120.2 ± 15.2 | 126.4 ± 14.3
Day 22 | 126.3 ± 31.4 | 80.7 ± 12.2 | 60.2 ± 6.9 | 83.4 ± 15.7 | 118.3 ± 45.0 | 108.3 ± 23.5
Week 14 | 166.9 ± 34.5 | 153.8 ± 36.7 | 164.2 ± 24.6 | 70.7 ± 7.0 | 237.5 ± 45.6 | 110.6 ± 24.9
Free fatty acids (mEq/L)
Day 4 | 0.529 ± 0.021 | 0.546 ± 0.044 | 0.471 ± 0.039^d^ | 0.492 ± 0.024 | 0.493 ± 0.016 | 0.507 ± 0.032
Day 22 | 0.449 ± 0.041 | 0.505 ± 0.025 | 0.440 ± 0.039 | 0.506 ± 0.045 | 0.495 ± 0.055 | 0.536 ± 0.030
Week 14 | 0.729 ± 0.038 | 0.854 ± 0.099 | 0.878 ± 0.085 | 0.779 ± 0.074 | 0.790 ± 0.075 | 0.781 ± 0.073
Female
Hematology
n
Day 4 | 10 | 10 | 10 | 10 | 10 | 10
Day 22 | 10 | 10 | 10 | 9 | 10 | 10
Week 14 | 10 | 9 | 10 | 10 | 10 | 10
Hematocrit (%)
Day 4 | 40.8 ± 1.0 | 40.5 ± 0.7 | 41.8 ± 0.7 | 41.0 ± 0.5 | 41.4 ± 0.8 | 42.0 ± 0.7
Day 22 | 45.9 ± 0.4 | 45.5 ± 0.4 | 46.7 ± 1.3 | 45.0 ± 0.4 | 46.3 ± 0.3 | 45.7 ± 0.5
Week 14 | 45.7 ± 0.8 | 46.9 ± 0.3 | 46.4 ± 0.3 | 47.2 ± 0.4 | 46.5 ± 0.4 | 46.6 ± 0.5
Hemoglobin (g/dL)
Day 4 | 13.9 ± 0.3 | 13.8 ± 0.2 | 14.2 ± 0.2 | 13.9 ± 0.2 | 14.1 ± 0.3 | 14.2 ± 0.2
Day 22 | 15.9 ± 0.1 | 15.6 ± 0.1 | 16.1 ± 0.4 | 15.5 ± 0.2 | 15.9 ± 0.1 | 15.7 ± 0.2
Week 14 | 16.0 ± 0.3 | 16.4 ± 0.1 | 16.3 ± 0.1 | 16.5 ± 0.2 | 16.3 ± 0.2 | 16.3 ± 0.2
Erythrocytes (10^6^/μL)
Day 4 | 6.97 ± 0.15 | 6.95 ± 0.10 | 7.16 ± 0.11 | 6.98 ± 0.10 | 7.08 ± 0.13 | 7.11 ± 0.13
Day 22 | 7.91 ± 0.08 | 7.83 ± 0.07 | 8.08 ± 0.21 | 7.73 ± 0.09 | 7.92 ± 0.06 | 7.79 ± 0.09
Week 14 | 8.72 ± 0.15 | 8.92 ± 0.05 | 8.82 ± 0.05 | 8.97 ± 0.08 | 8.82 ± 0.08 | 8.85 ± 0.09
Reticulocytes (10^6^/μL)
Day 4 | 0.40 ± 0.01 | 0.40 ± 0.02 | 0.41 ± 0.02 | 0.38 ± 0.02 | 0.41 ± 0.02 | 0.44 ± 0.02
Day 22 | 0.23 ± 0.01 | 0.21 ± 0.01 | 0.19 ± 0.01 | 0.22 ± 0.01 | 0.19 ± 0.01 | 0.20 ± 0.01
Week 14 | 0.17 ± 0.01 | 0.20 ± 0.01 | 0.20 ± 0.01 | 0.20 ± 0.01 | 0.20 ± 0.01 | 0.20 ± 0.01
Mean cell volume (fL)
Day 4 | 58.6 ± 0.2 | 58.2 ± 0.2 | 58.3 ± 0.3 | 58.8 ± 0.2 | 58.5 ± 0.2 | 58.9 ± 0.2
Day 22 | 58.2 ± 0.3 | 58.2 ± 0.2 | 57.7 ± 0.2 | 58.2 ± 0.2 | 58.3 ± 0.3 | 58.7 ± 0.3
Week 14 | 52.4 ± 0.2 | 52.6 ± 0.2 | 52.7 ± 0.2 | 52.6 ± 0.2 | 52.8 ± 0.1 | 52.5 ± 0.2
Mean cell hemoglobin (pg)
Day 4 | 19.9 ± 0.1 | 19.9 ± 0.1 | 19.8 ± 0.1 | 19.9 ± 0.1 | 19.9 ± 0.1 | 20.0 ± 0.1
Day 22 | 20.1 ± 0.1 | 19.9 ± 0.1 | 19.9 ± 0.1 | 20.1 ± 0.1 | 20.0 ± 0.1 | 20.2 ± 0.1
Week 14 | 18.4 ± 0.1 | 18.4 ± 0.0 | 18.5 ± 0.0 | 18.4 ± 0.0 | 18.5 ± 0.1 | 18.5 ± 0.0
Mean cell hemoglobin concentration (g/dL)
Day 4 | 34.1 ± 0.1 | 34.1 ± 0.1 | 33.9 ± 0.1 | 33.8 ± 0.1 | 34.1 ± 0.1 | 33.9 ± 0.1
Day 22 | 34.6 ± 0.1 | 34.3 ± 0.1 | 34.5 ± 0.1 | 34.5 ± 0.1 | 34.3 ± 0.1 | 34.4 ± 0.1
Week 14 | 35.2 ± 0.2 | 35.1 ± 0.1 | 35.1 ± 0.1 | 35.1 ± 0.1 | 35.1 ± 0.1 | 35.1 ± 0.1
Platelets (10^3^/μL)
Day 4 | 572.6 ± 22.5 | 521.4 ± 24.1 | 545.3 ± 14.9 | 559.7 ± 11.4 | 555.3 ± 14.8 | 562.5 ± 23.1
Day 22 | 510.5 ± 20.1 | 482.2 ± 19.1 | 465.2 ± 28.6 | 487.3 ± 20.4 | 485.4 ± 23.5 | 448.3 ± 26.4
Week 14 | 522.6 ± 23.9 | 503.6 ± 21.3 | 506.3 ± 18.5 | 552.5 ± 11.9 | 520.6 ± 14.6 | 551.2 ± 10.5
Leukocytes (10^3^/μL)
Day 4 | 9.58 ± 0.50 | 10.09 ± 0.65 | 9.93 ± 0.48 | 11.31 ± 0.73 | 9.94 ± 0.70 | 11.33 ± 0.39
Day 22 | 10.96 ± 0.73 | 11.70 ± 0.91 | 11.03 ± 0.64 | 11.37 ± 0.39 | 10.14 ± 0.47 | 11.41 ± 0.91
Week 14 | 6.94 ± 0.52 | 7.11 ± 0.65 | 8.17 ± 0.48 | 7.10 ± 0.62 | 7.38 ± 0.64 | 5.72 ± 0.43
Segmented neutrophils (10^3^/μL)
Day 4 | 1.02 ± 0.05 | 1.04 ± 0.08 | 0.97 ± 0.04 | 1.23 ± 0.07 | 1.06 ± 0.11 | 1.06 ± 0.06
Day 22 | 1.04 ± 0.06 | 1.09 ± 0.08 | 1.07 ± 0.06 | 1.12 ± 0.08 | 1.13 ± 0.10 | 1.22 ± 0.20
Week 14 | 1.83 ± 0.19 | 1.66 ± 0.17 | 2.13 ± 0.20 | 1.83 ± 0.16 | 1.84 ± 0.16 | 1.30 ± 0.13
Lymphocytes (10^3^/μL)
Day 4 | 7.65 ± 0.42 | 8.15 ± 0.58 | 8.14 ± 0.40 | 9.06 ± 0.56 | 7.92 ± 0.49 | 9.31 ± 0.40
Day 22 | 9.06 ± 0.63 | 9.48 ± 0.72 | 9.03 ± 0.60 | 9.40 ± 0.30 | 8.19 ± 0.37 | 9.22 ± 0.71
Week 14 | 4.53 ± 0.30 | 4.88 ± 0.47 | 5.39 ± 0.26 | 4.65 ± 0.45 | 4.96 ± 0.45 | 3.98 ± 0.27
Monocytes (10^3^/μL)
Day 4 | 0.55 ± 0.04 | 0.61 ± 0.05 | 0.62 ± 0.05 | 0.71 ± 0.09 | 0.66 ± 0.07 | 0.71 ± 0.04
Day 22 | 0.60 ± 0.06 | 0.79 ± 0.11 | 0.65 ± 0.05 | 0.55 ± 0.04 | 0.57 ± 0.05 | 0.59 ± 0.06
Week 14 | 0.36 ± 0.05 | 0.37 ± 0.05 | 0.44 ± 0.05 | 0.40 ± 0.06 | 0.37 ± 0.05 | 0.26 ± 0.04
Basophils (10^3^/μL)
Day 4 | 0.296 ± 0.087 | 0.267 ± 0.041 | 0.184 ± 0.017 | 0.286 ± 0.050 | 0.259 ± 0.051 | 0.214 ± 0.010
Day 22 | 0.212 ± 0.025 | 0.299 ± 0.060 | 0.217 ± 0.013 | 0.251 ± 0.029 | 0.208 ± 0.017 | 0.333 ± 0.096
Week 14 | 0.134 ± 0.015 | 0.122 ± 0.012 | 0.129 ± 0.013 | 0.129 ± 0.014 | 0.118 ± 0.017 | 0.095 ± 0.009
Eosinophils (10^3^/μL)
Day 4 | 0.05 ± 0.01 | 0.04 ± 0.00 | 0.03 ± 0.01 | 0.03 ± 0.01 | 0.05 ± 0.02 | 0.03 ± 0.01
Day 22 | 0.05 ± 0.01 | 0.04 ± 0.01 | 0.05 ± 0.01 | 0.05 ± 0.01 | 0.05 ± 0.00 | 0.05 ± 0.01
Week 14 | 0.07 ± 0.01 | 0.06 ± 0.01 | 0.08 ± 0.01 | 0.08 ± 0.01 | 0.09 ± 0.02 | 0.07 ± 0.01
Clinical Chemistry
n | 10 | 10 | 10 | 10 | 10 | 10
Urea nitrogen (mg/dL)
Day 4 | 17.6 ± 0.8 | 16.9 ± 0.5 | 16.2 ± 0.4 | 15.8 ± 0.7 | 16.4 ± 0.7 | 15.7 ± 0.5
Day 22 | 21.5 ± 0.6 | 21.1 ± 0.5 | 21.3 ± 0.8 | 20.6 ± 0.9 | 20.8 ± 1.0 | 22.4 ± 0.5
Week 14 | 18.5 ± 0.9 | 18.1 ± 0.7 | 19.8 ± 0.7 | 18.5 ± 0.5 | 20.1 ± 0.5 | 21.1 ± 0.7*
Creatinine (mg/dL)
Day 4 | 0.32 ± 0.01 | 0.31 ± 0.02 | 0.31 ± 0.01 | 0.28 ± 0.01 | 0.29 ± 0.01 | 0.32 ± 0.02
Day 22 | 0.36 ± 0.02 | 0.34 ± 0.02 | 0.34 ± 0.02 | 0.31 ± 0.01 | 0.36 ± 0.02 | 0.30 ± 0.00*
Week 14 | 0.39 ± 0.02 | 0.42 ± 0.02 | 0.37 ± 0.02 | 0.38 ± 0.01 | 0.40 ± 0.02 | 0.40 ± 0.02
Total protein (g/dL)
Day 4 | 6.1 ± 0.1 | 6.1 ± 0.1 | 6.2 ± 0.1 | 6.2 ± 0.1 | 6.2 ± 0.1 | 6.2 ± 0.1
Day 22 | 6.6 ± 0.1 | 6.2 ± 0.1 | 6.5 ± 0.1 | 6.3 ± 0.1 | 6.5 ± 0.1 | 6.6 ± 0.1
Week 14 | 6.6 ± 0.1 | 6.8 ± 0.1 | 6.8 ± 0.1 | 6.7 ± 0.1 | 6.7 ± 0.1 | 6.8 ± 0.1
Albumin (g/dL)
Day 4 | 4.2 ± 0.1 | 4.2 ± 0.1 | 4.3 ± 0.1 | 4.3 ± 0.1 | 4.3 ± 0.1 | 4.4 ± 0.1
Day 22 | 4.6 ± 0.1 | 4.4 ± 0.1 | 4.6 ± 0.1 | 4.5 ± 0.0 | 4.6 ± 0.0 | 4.7 ± 0.1
Week 14 | 4.5 ± 0.1 | 4.6 ± 0.1 | 4.7 ± 0.1 | 4.6 ± 0.1 | 4.6 ± 0.0 | 4.6 ± 0.0
Globulin (g/dL)
Day 4 | 1.8 ± 0.0 | 1.8 ± 0.0 | 1.9 ± 0.0 | 1.9 ± 0.0 | 1.9 ± 0.1 | 1.9 ± 0.0
Day 22 | 1.9 ± 0.1 | 1.8 ± 0.1 | 1.9 ± 0.0 | 1.8 ± 0.0* | 1.9 ± 0.0 | 1.9 ± 0.0
Week 14 | 2.1 ± 0.1 | 2.2 ± 0.0 | 2.1 ± 0.1 | 2.1 ± 0.0 | 2.1 ± 0.0 | 2.2 ± 0.0
Albumin/globulin ratio
Day 4 | 2.3 ± 0.0 | 2.3 ± 0.0 | 2.3 ± 0.0 | 2.4 ± 0.1 | 2.2 ± 0.1 | 2.3 ± 0.0
Day 22 | 2.5 ± 0.1 | 2.5 ± 0.1 | 2.5 ± 0.1 | 2.5 ± 0.0 | 2.5 ± 0.1 | 2.5 ± 0.1
Week 14 | 2.2 ± 0.1 | 2.2 ± 0.0 | 2.2 ± 0.0 | 2.2 ± 0.0 | 2.2 ± 0.0 | 2.1 ± 0.0
Cholesterol (mg/dL)
Day 4 | 109 ± 4 | 110 ± 5 | 108 ± 3 | 118 ± 3 | 112 ± 4 | 113 ± 3
Day 22 | 99 ± 3 | 94 ± 3 | 98 ± 2 | 93 ± 2 | 97 ± 2 | 92 ± 5
Week 14 | 96 ± 2 | 101 ± 2 | 104 ± 3 | 103 ± 3 | 96 ± 3 | 98 ± 3
Alanine aminotransferase (IU/L)
Day 4 | 52 ± 2 | 51 ± 2 | 54 ± 2 | 54 ± 1 | 56 ± 2 | 59 ± 2
Day 22 | 48 ± 1 | 49 ± 2 | 47 ± 3 | 46 ± 1 | 50 ± 2 | 52 ± 4
Week 14 | 67 ± 10 | 79 ± 5 | 66 ± 5 | 70 ± 5 | 74 ± 4 | 78 ± 5
Alkaline phosphatase (IU/L)
Day 4 | 708 ± 16 | 690 ± 22 | 713 ± 19 | 717 ± 11 | 684 ± 17 | 689 ± 19
Day 22 | 500 ± 12 | 487 ± 11 | 499 ± 12 | 499 ± 11 | 516 ± 10 | 481 ± 19
Week 14 | 201 ± 6 | 193 ± 5 | 217 ± 11 | 197 ± 5 | 216 ± 7 | 204 ± 8
Creatine kinase (IU/L)
Day 4 | 215 ± 29^c^ | 268 ± 38 | 251 ± 35 | 192 ± 15 | 292 ± 63 | 191 ± 24
Day 22 | 192 ± 18^c^ | 273 ± 52 | 213 ± 33 | 304 ± 55 | 236 ± 23 | 200 ± 22
Week 14 | 139 ± 14 | 233 ± 74 | 161 ± 21 | 129 ± 14 | 222 ± 36 | 205 ± 40
Sorbitol dehydrogenase (IU/L)
Day 4 | 15 ± 1 | 15 ± 1 | 15 ± 1 | 16 ± 1 | 15 ± 1 | 16 ± 1
Day 22 | 17 ± 1 | 17 ± 1 | 19 ± 2 | 17 ± 1 | 20 ± 1 | 18 ± 1
Week 14 | 15 ± 2 | 16 ± 2 | 14 ± 1 | 14 ± 1 | 15 ± 1 | 16 ± 1
Bile acids (µmol/L)
Day 4 | 23.2 ± 1.6 | 26.9 ± 2.5 | 29.8 ± 3.4 | 24.4 ± 2.1 | 24.3 ± 1.8 | 29.0 ± 2.9
Day 22 | 25.6 ± 3.5 | 29.0 ± 2.4 | 30.8 ± 2.6 | 25.7 ± 2.4 | 22.4 ± 0.4 | 28.7 ± 1.3
Week 14 | 57.2 ± 9.7 | 62.5 ± 6.9 | 69.7 ± 6.6 | 60.5 ± 6.1 | 63.2 ± 5.6 | 70.2 ± 3.3
3-Hydroxybutyrate (µmol/L)
Day 4 | 121.2 ± 14.6 | 118.6 ± 9.6 | 136.0 ± 7.4 | 102.6 ± 8.6 | 128.7 ± 14.7 | 138.3 ± 22.9
Day 22 | 109.2 ± 14.4 | 83.8 ± 6.4 | 102.0 ± 9.7^c^ | 100.7 ± 13.4 | 123.0 ± 18.7 | 96.9 ± 5.9
Week 14 | 323.7 ± 52.9 | 341.2 ± 44.3 | 172.9 ± 40.3 | 269.3 ± 52.5 | 221.0 ± 40.1 | 351.3 ± 45.6
Free fatty acids (mEq/L)
Day 4 | 0.629 ± 0.116 | 0.611 ± 0.051 | 0.615 ± 0.045 | 0.635 ± 0.025 | 0.561 ± 0.041 | 0.614 ± 0.057
Day 22 | 0.419 ± 0.029 | 0.452 ± 0.041 | 0.524 ± 0.038 | 0.513 ± 0.036 | 0.493 ± 0.019 | 0.504 ± 0.038
Week 14 | 0.895 ± 0.076 | 0.974 ± 0.067 | 0.927 ± 0.105 | 0.907 ± 0.110 | 0.856 ± 0.057 | 0.990 ± 0.056

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Ratios were calculated and statistical tests were performed on unrounded data.

^b^ n = 7.

^c^ n = 9.

^d^ n = 1.

Table C-2 Hematology Data for Mice in the Three-month Dermal Study of Sodium Thioglycolate^a^

| Vehicle Control | 22.5 mg/kg | 45 mg/kg | 90 mg/kg | 180 mg/kg | 360 mg/kg
Male
n | 10 | 10 | 9 | 10 | 10 | 10
Hematocrit (%) | 50.9 ± 0.6 | 50.8 ± 0.5 | 50.9 ± 0.5 | 51.0 ± 0.5 | 51.3 ± 0.5 | 49.8 ± 0.7
Hemoglobin (g/dL) | 16.9 ± 0.2 | 16.8 ± 0.2 | 16.9 ± 0.2 | 16.9 ± 0.2 | 16.9 ± 0.1 | 16.4 ± 0.2
Erythrocytes (10^6^/µL) | 10.88 ± 0.11 | 10.85 ± 0.08 | 10.85 ± 0.13 | 10.93 ± 0.12 | 10.90 ± 0.09 | 10.51 ± 0.10*
Reticulocytes (10^6^/µL) | 0.26 ± 0.02 | 0.27 ± 0.01 | 0.28 ± 0.02 | 0.26 ± 0.02 | 0.27 ± 0.01 | 0.26 ± 0.01
Mean cell volume (fL) | 46.2 ± 0.3 | 46.7 ± 0.3 | 46.9 ± 0.2 | 46.7 ± 0.2 | 47.1 ± 0.2** | 47.5 ± 0.3**
Mean cell hemoglobin (pg) | 15.3 ± 0.1 | 15.4 ± 0.1 | 15.6 ± 0.1 | 15.4 ± 0.1 | 15.5 ± 0.1* | 15.6 ± 0.1**
Mean cell hemoglobin concentration (g/dL) | 33.1 ± 0.1 | 33.1 ± 0.1 | 33.2 ± 0.1 | 33.1 ± 0.1 | 33.0 ± 0.1 | 33.0 ± 0.1
Platelets (10^3^/µL) | 629.3 ± 24.8 | 605.3 ± 30.7 | 636.4 ± 15.9 | 579.3 ± 24.7 | 634.7 ± 15.6 | 582.8 ± 30.1
Leukocytes (10^3^/µL) | 7.35 ± 0.49 | 7.22 ± 0.69 | 8.64 ± 0.74 | 7.49 ± 0.74 | 6.88 ± 0.53 | 7.51 ± 0.62
Segmented neutrophils (10^3^/µL) | 0.51 ± 0.06 | 0.47 ± 0.08 | 0.59 ± 0.12 | 0.48 ± 0.06 | 0.42 ± 0.05 | 0.53 ± 0.09
Lymphocytes (10^3^/µL) | 6.46 ± 0.45 | 6.39 ± 0.57 | 7.68 ± 0.62 | 6.70 ± 0.68 | 6.13 ± 0.46 | 6.57 ± 0.53
Monocytes (10^3^/µL) | 0.20 ± 0.04 | 0.15 ± 0.02 | 0.18 ± 0.02 | 0.15 ± 0.02 | 0.15 ± 0.02 | 0.17 ± 0.02
Basophils (10^3^/µL) | 0.117 ± 0.020 | 0.156 ± 0.039 | 0.133 ± 0.026 | 0.111 ± 0.021 | 0.118 ± 0.025 | 0.161 ± 0.049
Eosinophils (10^3^/µL) | 0.06 ± 0.01 | 0.08 ± 0.02 | 0.06 ± 0.01 | 0.05 ± 0.01 | 0.05 ± 0.01 | 0.07 ± 0.03
Female
n | 10 | 10 | 10 | 10 | 10 | 10
Hematocrit (%) | 54.6 ± 0.5 | 51.1 ± 0.6** | 51.7 ± 0.5** | 53.3 ± 0.7 | 52.6 ± 0.6 | 51.1 ± 0.6**
Hemoglobin (g/dL) | 17.8 ± 0.2 | 16.9 ± 0.2** | 17.0 ± 0.1** | 17.4 ± 0.2 | 17.3 ± 0.2 | 16.8 ± 0.2**
Erythrocytes (10^6^/µL) | 11.21 ± 0.14 | 10.59 ± 0.14** | 10.66 ± 0.08** | 10.88 ± 0.13* | 10.78 ± 0.11* | 10.37 ± 0.11**
Reticulocytes (10^6^/µL) | 0.28 ± 0.01 | 0.25 ± 0.02 | 0.26 ± 0.02 | 0.28 ± 0.02 | 0.28 ± 0.01 | 0.26 ± 0.02
Mean cell volume (fL) | 48.9 ± 0.2 | 48.3 ± 0.3 | 48.4 ± 0.2 | 49.0 ± 0.3 | 49.1 ± 0.2 | 49.3 ± 0.2
Mean cell hemoglobin (pg) | 15.9 ± 0.1 | 16.0 ± 0.1 | 15.9 ± 0.1 | 16.0 ± 0.1 | 16.1 ± 0.1* | 16.2 ± 0.1**
Mean cell hemoglobin concentration (g/dL) | 32.7 ± 0.1 | 33.1 ± 0.1 | 32.9 ± 0.1 | 32.6 ± 0.2 | 33.0 ± 0.1 | 32.9 ± 0.1
Platelets (10^3^/µL) | 495.7 ± 25.8 | 495.8 ± 32.8 | 514.9 ± 22.1 | 489.1 ± 28.8 | 465.6 ± 30.2 | 511.3 ± 36.5
Leukocytes (10^3^/µL) | 6.95 ± 0.35 | 6.50 ± 0.71 | 6.37 ± 0.56 | 7.84 ± 0.65 | 6.65 ± 0.34 | 5.88 ± 0.49
Segmented neutrophils (10^3^/µL) | 0.33 ± 0.02 | 0.36 ± 0.05 | 0.46 ± 0.07 | 0.55 ± 0.09 | 0.40 ± 0.06 | 0.30 ± 0.02
Lymphocytes (10^3^/µL) | 6.37 ± 0.32 | 5.83 ± 0.64 | 5.53 ± 0.49 | 6.80 ± 0.55 | 5.96 ± 0.31 | 5.34 ± 0.45
Monocytes (10^3^/µL) | 0.16 ± 0.01 | 0.19 ± 0.02 | 0.17 ± 0.02 | 0.21 ± 0.02 | 0.15 ± 0.02 | 0.16 ± 0.02
Basophils (10^3^/µL) | 0.052 ± 0.010 | 0.092 ± 0.021 | 0.128 ± 0.034 | 0.180 ± 0.055 | 0.103 ± 0.032 | 0.055 ± 0.008
Eosinophils (10^3^/µL) | 0.02 ± 0.00 | 0.05 ± 0.01 | 0.06 ± 0.02 | 0.09 ± 0.03 | 0.04 ± 0.01 | 0.03 ± 0.00

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunn’s or Shirley’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.