# Appendix B Genetic Toxicology

Table B-1 Mutagenicity of Sodium Thioglycolate in Salmonella typhimurium^a^

Strain | Dose (μg/plate) | Without S9 | Without S9 | With 10% Hamster S9 | With 10% Hamster S9 | With 10% Rat S9 | With 10% Rat S9
TA100
| 0 | 100 ± 5 | 110 ± 6 | 185 ± 26 | 179 ± 12 | 175 ± 28 | 189 ± 9
| 10 | 95 ± 5 | 126 ± 11 | 160 ± 18 | 164 ± 6 | 140 ± 30 | 204 ± 38
| 33 | 105 ± 31 | 129 ± 8 | 195 ± 30 | 174 ± 8 | 170 ± 41 | 189 ± 4
| 100 | 115 ± 10 | 121 ± 4 | 220 ± 18 | 221 ± 4 | 145 ± 18 | 175 ± 9
| 333 | 125 ± 13 | 122 ± 8 | 160 ± 5 | 173 ± 10 | 135 ± 9 | 221 ± 8
| 1,000 | 120 ± 30 | 124 ± 9 | 215 ± 13 | 202 ± 4 | 155 ± 35 | 181 ± 18
Trial summary | | Negative | Negative | Negative | Equivocal | Negative | Negative
Positive control^b^ | | 430 ± 28 | 599 ± 36 | 558 ± 6 | 836 ± 173 | 300 ± 11 | 430 ± 70
TA1535
| 0 | 7 ± 1 | 7 ± 1 | 6 ± 1 | 7 ± 3 | 7 ± 1
| 10 | 6 ± 1 | 6 ± 1 | 5 ± 1 | 6 ± 2 | 8 ± 1
| 33 | 5 ± 1 | 6 ± 1 | 7 ± 2 | 9 ± 1 | 6 ± 1
| 100 | 8 ± 4 | 9 ± 1 | 7 ± 1 | 9 ± 1 | 6 ± 1
| 333 | 6 ± 1 | 6 ± 1 | 5 ± 1 | 7 ± 2 | 8 ± 1
| 1,000 | 5 ± 1 | 8 ± 2 | 5 ± 0 | 8 ± 1 | 8 ± 1
Trial summary | | Negative | Negative | Negative | Negative | Negative
Positive control | | 288 ± 32 | 251 ± 41 | 106 ± 16 | 43 ± 4 | 135 ± 10
TA1537
| 0 | 6 ± 3 | 5 ± 1 | 8 ± 1 | 12 ± 2 | 5 ± 1 | 7 ± 2
| 10 | 7 ± 1 | 6 ± 1 | 4 ± 1 | 9 ± 3 | 4 ± 1 | 8 ± 2
| 33 | 6 ± 1 | 6 ± 1 | 6 ± 0 | 11 ± 2 | 8 ± 2 | 12 ± 2
| 100 | 5 ± 1 | 3 ± 2 | 5 ± 1 | 6 ± 1 | 6 ± 2 | 8 ± 2
| 333 | 6 ± 1 | 8 ± 2 | 6 ± 1 | 9 ± 3 | 5 ± 1 | 9 ± 1
| 1,000 | 7 ± 2 | 6 ± 0 | 6 ± 0 | 9 ± 0 | 6 ± 1 | 10 ± 2
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control | | 133 ± 12 | 248 ± 79 | 92 ± 9 | 48 ± 7 | 48 ± 8 | 60 ± 29
TA98
| 0 | 17 ± 2 | 14 ± 2 | 22 ± 2 | 21 ± 1 | 18 ± 2 | 16 ± 1
| 10 | 17 ± 2 | 11 ± 2 | 25 ± 2 | 19 ± 4 | 27 ± 5 | 20 ± 2
| 33 | 21 ± 2 | 14 ± 2 | 23 ± 2 | 16 ± 3 | 15 ± 3 | 18 ± 3
| 100 | 21 ± 3 | 13 ± 2 | 18 ± 2 | 17 ± 1 | 18 ± 3 | 15 ± 1
| 333 | 20 ± 2 | 13 ± 2 | 23 ± 2 | 19 ± 2 | 19 ± 3 | 15 ± 1
| 1,000 | 22 ± 3 | 14 ± 3 | 18 ± 3 | 18 ± 1 | 16 ± 1 | 16 ± 3
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control | | 246 ± 23 | 256 ± 44 | 468 ± 16 | 444 ± 51 | 142 ± 23 | 134 ± 15

^a^ Data are presented as revertants/plate (mean ± standard error) from three plates. Study was performed at Case Western Reserve University. The detailed protocol and these data are presented by Zeiger et al.27 0 μg/plate was the solvent control.

^b^ The positive controls in the absence of metabolic activation were sodium azide (TA100 and TA1535), 9-aminoacridine (TA1537), and 4-nitro-o-phenylenediamine (TA98). The positive control for metabolic activation with all strains was 2-aminoanthracene.

Table B-2 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Mice Following Dermal Application of Sodium Thioglycolate for Three Months^a^

| Dose (mg/kg) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs^b^ (%)
Male
95% Ethanol:deionized water^d^ | | 5 | 3.4 ± 0.29 | | 3.20 ± 0.18
Sodium thioglycolate | 22.5 | 5 | 4.1 ± 0.51 | 0.2090 | 3.28 ± 0.11
| 45 | 5 | 4.6 ± 0.73 | 0.0894 | 4.08 ± 0.23
| 90 | 5 | 4.3 ± 0.56 | 0.1521 | 4.04 ± 0.35
| 180 | 5 | 4.0 ± 0.16 | 0.2423 | 3.80 ± 0.43
| 360 | 5 | 4.4 ± 0.37 | 0.1283 | 3.58 ± 0.29
| | | P = 0.290^e^
Female
95% Ethanol:deionized water | | 5 | 2.1 ± 0.10 | | 3.88 ± 0.17
Sodium thioglycolate | 22.5 | 5 | 3.0 ± 0.32 | 0.1035 | 3.22 ± 0.26
| 45 | 5 | 2.6 ± 0.24 | 0.2326 | 3.48 ± 0.44
| 90 | 5 | 3.1 ± 0.48 | 0.0825 | 2.68 ± 0.15
| 180 | 5 | 3.3 ± 0.20 | 0.0510 | 3.30 ± 0.44
| 360 | 5 | 4.4 ± 0.29 | 0.0021 | 3.32 ± 0.18
| | | P = 0.002

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by MacGregor et al.41 NCE = normochromatic erythrocyte; PCE = polychromatic erythrocyte.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the vehicle control group; dosed group values are significant at P ≤ 0.005.

^d^ Vehicle control at a 1:1 ratio.

^e^ Significance of micronucleated NCEs/1,000 NCEs tested by the one-tailed trend test; significant at P ≤ 0.025.