# Appendix A Summary of Neoplasms and Nonneoplastic Lesions in Rats and Mice

Table A-1 Summary of the Incidence of Nonneoplastic Lesions in Male Rats in the Three-month Dermal Study of Sodium Thioglycolate^a^

| Vehicle Control | 11.25 mg/kg | 22.5 mg/kg | 45 mg/kg | 90 mg/kg | 180 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Survivors
Terminal kill | 10 | 10 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | – | – | – | – | (10)
Hepatodiaphragmatic nodule | – | – | – | – | – | 1 (10%)
Cardiovascular System
Heart | (10) | – | – | – | – | (10)
Cardiomyopathy | 3 (30%) | – | – | – | – | 1 (10%)
Endocrine System
Adrenal cortex | (10) | – | – | – | – | (10)
Zona fasciculata, vacuolization cytoplasmic | 10 (100%) | – | – | – | – | 10 (100%)
General Body System
None | – | – | – | – | – | –
Genital System
None | – | – | – | – | – | –
Hematopoietic System
Spleen | (10) | – | – | – | – | (10)
Congestion | 9 (90%) | – | – | – | – | 10 (100%)
Hematopoietic cell proliferation | 10 (100%) | – | – | – | – | 10 (100%)
Pigmentation | 9 (90%) | – | – | – | – | 10 (100%)
Thymus | (10) | – | – | – | – | (10)
Hemorrhage, focal | 1 (10%) | – | – | – | – | 1 (10%)
Thymocyte, atrophy | – | – | – | – | – | 1 (10%)
Integumentary System
Skin | (10) | (10) | (10) | (10) | (10) | (10)
Sebaceous gland, site of application, dermis, hypertrophy | – | – | 2 (20%) | 4 (40%) | 5 (50%) | 6 (60%)
Site of application, epidermis, exudate, focal | – | – | – | – | – | 1 (10%)
Site of application, epidermis, hyperkeratosis | – | 6 (60%) | 9 (90%) | 4 (40%) | 4 (40%) | 4 (40%)
Site of application, epidermis, hyperplasia, diffuse | – | 1 (10%) | 2 (20%) | 3 (30%) | 5 (50%) | 6 (60%)
Site of application, epidermis, hyperplasia, focal | – | – | – | – | 1 (10%) | –
Site of application, epidermis, parakeratosis, focal | 1 (10%) | – | – | – | – | –
Musculoskeletal System
None | – | – | – | – | – | –
Nervous System
None | – | – | – | – | – | –
Respiratory System
Lung | (10) | – | – | – | – | (10)
Hemorrhage, focal | 1 (10%) | – | – | – | – | –
Alveolus, hemorrhage, focal | – | – | – | – | – | 1 (10%)
Alveolus, infiltration cellular, histiocyte | – | – | – | – | – | 1 (10%)
Alveolus, inflammation, chronic active, focal | 2 (20%) | – | – | – | – | –
Special Senses System
None | – | – | – | – | – | –
Urinary System
Kidney | (10) | – | – | – | – | (10)
Nephropathy | 3 (30%) | – | – | – | – | –
Nephropathy, focal | – | – | – | – | – | 1 (10%)
Renal tubule, regeneration, focal | 1 (10%) | – | – | – | – | 2 (20%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesions.

Table A-2 Summary of the Incidence of Neoplasms and Nonneoplastic Lesions in Female Rats in the Three-month Dermal Study of Sodium Thioglycolate^a^

| Vehicle Control | 11.25 mg/kg | 22.5 mg/kg | 45 mg/kg | 90 mg/kg | 180 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Survivors
Terminal kill | 10 | 10 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | – | – | – | – | (10)
Hepatodiaphragmatic nodule | – | – | – | – | – | 2 (20%)
Inflammation, granulomatous | 1 (10%) | – | – | – | – | 3 (30%)
Necrosis, focal | 1 (10%) | – | – | – | – | –
Pancreas | (10) | – | – | – | – | (10)
Atrophy, focal | 1 (10%) | – | – | – | – | –
Cardiovascular System
Heart | (10) | – | – | – | – | (10)
Cardiomyopathy | 1 (10%) | – | – | – | – | –
Endocrine System
Pituitary gland | (10) | – | – | – | – | (10)
Cyst | – | – | – | – | – | 1 (10%)
Thyroid gland | (9) | – | – | – | – | (9)
Ectopic thymus | 1 (11%) | – | – | – | – | 2 (22%)
General Body System
None | – | – | – | – | – | –
Genital System
Uterus | (10) | – | – | – | – | (10)
Dilatation | 2 (20%) | – | – | – | – | 4 (40%)
Hematopoietic System
Lymph node | (1) | – | – | – | – | (3)
Hemorrhage | – | – | – | – | – | 1 (33%)
Pancreatic, inflammation, granulomatous | 1 (100%) | – | – | – | – | –
Thoracic, hyperplasia, lymphoid | – | – | – | – | – | 2 (67%)
Lymph node, mesenteric | (10) | – | – | – | – | (10)
Inflammation, granulomatous | – | – | – | – | – | 1 (10%)
Spleen | (10) | – | – | – | – | (10)
Congestion | 10 (100%) | – | – | – | – | 10 (100%)
Hematopoietic cell proliferation | 10 (100%) | – | – | – | – | 10 (100%)
Pigmentation | 9 (90%) | – | – | – | – | 10 (100%)
Thymus | (10) | – | – | – | – | (10)
Thymocyte, atrophy | 4 (40%) | – | – | – | – | 3 (30%)
Integumentary System
Skin | (10) | (10) | (10) | (10) | (10) | (10)
Sebaceous gland, site of application, dermis, hypertrophy | – | – | – | 2 (20%) | 6 (60%) | 5 (50%)
Site of application, epidermis, hyperkeratosis | – | – | 1 (10%) | 7 (70%) | 6 (60%) | 5 (50%)
Site of application, epidermis, hyperplasia, diffuse | – | – | – | 2 (20%) | 7 (70%) | 8 (80%)
Site of application, epidermis, infiltration cellular, mononuclear cell | – | – | – | – | 1 (10%) | –
Site of application, epidermis, parakeratosis, focal | – | – | – | – | – | 3 (30%)
Site of application, epidermis, ulcer, focal | – | – | – | – | – | 3 (30%)
Musculoskeletal System
None | – | – | – | – | – | –
Nervous System
None | – | – | – | – | – | –
Respiratory System
None | – | – | – | – | – | –
Special Senses System
Harderian gland | (10) | – | – | – | – | (10)
Infiltration cellular, lymphocyte | – | – | – | – | – | 1 (10%)
Urinary System
Kidney | (10) | – | – | – | – | (10)
Nephroblastoma | 1 (10%) | – | – | – | – | –
Renal tubule, regeneration, focal | – | – | – | – | – | 2 (20%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.

Table A-3 Summary of the Incidence of Nonneoplastic Lesions in Male Mice in the Three-month Dermal Study of Sodium Thioglycolate^a^

| Vehicle Control | 22.5 mg/kg | 45 mg/kg | 90 mg/kg | 180 mg/kg | 360 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Survivors
Terminal kill | 10 | 10 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | – | – | – | – | (10)
Inflammation, chronic active | 1 (10%) | – | – | – | – | –
Cardiovascular System
None | – | – | – | – | – | –
Endocrine System
Adrenal cortex | (10) | – | – | – | – | (10)
Subcapsular, hyperplasia | 2 (20%) | – | – | – | – | 3 (30%)
Thyroid gland | (9) | – | – | – | – | (9)
Ectopic thymus | – | – | – | – | – | 1 (11%)
General Body System
None | – | – | – | – | – | –
Genital System
None | – | – | – | – | – | –
Hematopoietic System
Spleen | (10) | – | – | – | – | (10)
Hematopoietic cell proliferation | 10 (100%) | – | – | – | – | 10 (100%)
Thymus | (7) | – | – | – | – | (10)
Thymocyte, atrophy | 1 (14%) | – | – | – | – | –
Integumentary System
Skin | (10) | (10) | (10) | (10) | (10) | (10)
Sebaceous gland, site of application, dermis, hypertrophy | – | – | – | – | 2 (20%) | 4 (40%)
Site of application, epidermis, hyperkeratosis | – | – | – | – | 3 (30%) | 3 (30%)
Site of application, epidermis, hyperplasia, diffuse | – | – | – | – | 3 (30%) | 6 (60%)
Site of application, epidermis, hyperplasia, focal | – | – | 1 (10%) | – | 2 (20%) | 1 (10%)
Musculoskeletal System
None | – | – | – | – | – | –
Nervous System
None | – | – | – | – | – | –
Respiratory System
None | – | – | – | – | – | –
Special Senses System
None | – | – | – | – | – | –
Urinary System
Kidney | (10) | – | – | – | – | (10)
Renal tubule, regeneration | – | – | – | – | – | 2 (20%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesions.

Table A-4 Summary of the Incidence of Nonneoplastic Lesions in Female Mice in the Three-month Dermal Study of Sodium Thioglycolate^a^

| Vehicle Control | 22.5 mg/kg | 45 mg/kg | 90 mg/kg | 180 mg/kg | 360 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Survivors
Terminal kill | 10 | 10 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | – | – | – | – | (10)
Inflammation, chronic active | 2 (20%) | – | – | – | – | 5 (50%)
Necrosis, focal | – | – | – | – | – | 3 (30%)
Cardiovascular System
None | – | – | – | – | – | –
Endocrine System
Adrenal cortex | (10) | – | – | – | – | (10)
Subcapsular, hyperplasia | 10 (100%) | – | – | – | – | 10 (100%)
Thyroid gland | (10) | – | – | – | – | (10)
Ectopic thymus | – | – | – | – | – | 1 (10%)
General Body System
None | – | – | – | – | – | –
Genital System
Oviduct | (1) | – | – | – | – | –
Cyst | 1 (100%) | – | – | – | – | –
Uterus | (10) | – | – | – | – | (10)
Endometrium, hyperplasia, cystic | 4 (40%) | – | – | – | – | 4 (40%)
Hematopoietic System
Spleen | (10) | – | – | – | – | (10)
Hematopoietic cell proliferation | 8 (80%) | – | – | – | – | 10 (100%)
Thymus | (10) | – | – | – | – | (10)
Thymocyte, atrophy | – | – | – | – | – | 1 (10%)
Integumentary System
Skin | (10) | (10) | (10) | (10) | (10) | (10)
Sebaceous gland, site of application, dermis, hypertrophy | – | – | – | – | 6 (60%) | 7 (70%)
Site of application, dermis, hemorrhage, focal | – | 1 (10%) | – | – | – | –
Site of application, dermis, inflammation, chronic active | – | – | – | – | 1 (10%) | –
Site of application, dermis, inflammation, chronic active, focal | – | 1 (10%) | – | 1 (10%) | – | –
Site of application, epidermis, exudate | – | 1 (10%) | – | – | – | –
Site of application, epidermis, exudate, focal | – | – | 1 (10%) | – | – | –
Site of application, epidermis, hyperkeratosis | – | – | – | 1 (10%) | 1 (10%) | 4 (40%)
Site of application, epidermis, hyperplasia, diffuse | – | – | – | – | 6 (60%) | 8 (80%)
Site of application, epidermis, hyperplasia, focal | – | 1 (10%) | 3 (30%) | 1 (10%) | 3 (30%) | 2 (20%)
Site of application, epidermis, inflammation, chronic active | – | – | – | – | – | 1 (10%)
Site of application, epidermis, inflammation, chronic active, focal | – | – | 1 (10%) | – | – | –
Musculoskeletal System
None | – | – | – | – | – | –
Nervous System
Brain | (10) | – | – | – | – | (10)
Cyst epithelial inclusion | 1 (10%) | – | – | – | – | –
Respiratory System
None | – | – | – | – | – | –
Special Senses System
None | – | – | – | – | – | –
Urinary System
Kidney | (10) | – | – | – | – | (10)
Inflammation, chronic active | – | – | – | – | – | 1 (10%)
Renal tubule, casts protein | – | – | – | – | – | 1 (10%)
Renal tubule, regeneration | – | – | – | – | – | 1 (10%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.