# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2378-8992

DOI: https://doi.org/10.22427/NTP-TOX-78

Report Series: NTP Toxicity Report Series

Report Series Number: 78

Official citation: National Toxicology Program (NTP). 2018. NTP technical report on the toxicity studies of triethylamine (CASRN 121-44-8) administered by inhalation to F344/N rats and B6C3F1/N mice. Research Triangle Park, NC: National Toxicology Program. Toxicity Report 78.