# Peer Review

The draft NTP Technical Report on the Toxicity Studies of Triethylamine (CASRN 121-44-8) Administered by Inhalation to F344/N Rats and B6C3F1/N Mice was evaluated by the reviewers listed below. These reviewers served as independent scientists, not as representatives of any institution, company, or governmental agency. In this capacity, reviewers determined if the design and conditions of these NTP studies were appropriate and ensured that this NTP Toxicity Study Report presented the experimental results and conclusions fully and clearly.

## Peer Reviewers

- William J. Brock, Ph.D.
  Brock Scientific Consulting, LLC
  Montgomery Village, Maryland, USA
- Kymberly M. Gowdy, M.S., Ph.D.
  Department of Pharmacology and Toxicology
  Brody School of Medicine
  East Carolina University
  Greenville, North Carolina, USA
- Travis L. Knuckles, Ph.D.
  School of Public Health
  West Virginia University
  Morgantown, West Virginia, USA