# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  D.L. Morgan, Ph.D., Study Scientist
  G.P. Flake, M.D., Study Pathologist
  J.B. Bishop, Ph.D.
  C.R. Blystone, Ph.D.
  P.M. Foster, Ph.D.
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  G.E. Kissling, Ph.D.
  D.E. Malarkey, D.V.M., Ph.D.
  B.S. McIntyre, Ph.D.
  M.D. Stout, Ph.D.
  G.S. Travlos, D.V.M.
  M.K. Vallant, M.S., MT
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
  K.L. Witt, M.S.
- Coordinated NTP Pathology Peer Reviews for the reevaluation of nose and eye (2-week and 3-month studies) (February 28, 2014) and eye (2-week studies; August 7, 2015) (3-month rat study; November 17, 2015)
  G.P. Flake, M.D.
- Battelle Toxicology Northwest, Richland, Washington, USA
  Conducted studies and evaluated pathology findings
  J.A. Dill, Ph.D., Principal Investigator
  S.L. Grumbein, D.V.M., Ph.D.
  S.J. Harbo, D.V.M.
  B.K. Hayden
  R.A. Renne, D.V.M.
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Conducted pathology review
  M.M. Gruebbel, D.V.M., Ph.D.
  J.C. Peckham, D.V.M., Ph.D.
- Pathology Associates, a Division of Charles River Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Coordinated NTP Pathology Peer Review (3-month studies) (June 3, 2004)
  M.P. Jokinen, D.V.M.
- TherImmune Research Corporation, Gaithersburg, Maryland, USA
  Provided SMVCE analysis
  G.W. Wolfe, Ph.D., Principal Investigator
  B. Atkinson, M.S.
  H. Seung, M.S.