# References

1 American Conference of Governmental Industrial Hygienists (ACGIH). Documentation of the threshold limit values and biological exposure indices. Cincinnati, OH; 1986.
2 Lewis R Sax’s dangerous properties of industrial materials. New York (NY): Van Nostrand Reinhold; 1992.
3 Nelson MA Bull RJ Triethylamine. In: Buhler DR Reed DJeditors. Ethel Browning’s Toxicity and Metabolism of Industrial Solvents: Nitrogen and Phosphorus Solvents. 2nd ed. Netherlands: Elsevier Science; 1990. p. 129–133. 10.1016/B978-0-444-81316-9.50027-X
4 Schweizer AE Fowlkes RL McMakin JH Whyte TE Jr Aliphatic amines. In: Standen Aeditor. Kirk-Othmer Encyclopedia of Chemical Technology. 2nd ed. New York (NY): John Wiley & Sons; 1978. p. 272–283.
5 United States Environmental Protection Agency (USEPA). High Production Volume (HPV) challenge program. United States Environmental Protection Agency; 2007. https://www.epa.gov/hpv
6 International SRI (SRI). Alkylamines. United States, consumption, ethylamines, triethylamine. In: Chemical Economics Handbook. Menlo Park, CA: SRI International; 1997. DIALOG File 359.
7 MacBain G Strange RC Encyclopedia of Occupational Health and Safety. 3rd ed. Geneva, Switzerland: International Labour Office; 1983. Foundries; p. 916–923.
8 Warren DW Jr Selchan DF An industrial hygiene appraisal of triethylamine and dimethylethylamine exposure limits in the foundry industry. Am Ind Hyg Assoc J. 1988;49(12):630–634. 10.1080/15298668891380367 3213816
9 Conrard R Cold-box coremaking-ashland process. Les Cahiers De Notes Documentaires. Sécurité Et Hygiène Du Travail. 1977;87:195–203.
10 Kay R Survey into the fumes evolved from foundry sand binders based on synthetic resins. Br Foundryman. 1974;67:1–4.
11 Hansen MK Larsen M Cohr K-H Waterborne paints. A review of their chemistry and toxicology and the results of determinations made during their use. Scand J Work Environ Health. 1987;13(6):473–485. 10.5271/sjweh.2010 3324321
12 Sax N Sax’s Dangerous Properties of Industrial Materials. 10th ed. New York (NY): Van Nostrand Reinhold; 1994. Chemical review of triethylamine; p. 2–27.
13 National Institute for Occupational Safety and Health (NIOSH). National Occupational Exposure Survey (1981-1983) [unpublished provisional data]. Cincinnati, OH. 1990.
14 Code of Federal Regulations (CFR). 29:§1910.1000.
15 American Conference of Governmental Industrial Hygienists (ACGIH). 2012 TLVs® and BEIs®. Threshold limit values for chemical substances and physical agents and biological exposure indices. Cincinnati, OH; 2012.
16 National Institute for Occupational Safety and Health (NIOSH). Triethylamine. Atlanta, GA: Centers for Disease Control and Prevention, National Institute for Occupational Safety and Health; 2014. International Chemical Safety Card No. 0203. https://www.cdc.gov/niosh/ipcsneng/neng0203.html [Accessed: March 1, 2018]
17 Akesson B Skerfving S Mattiasson L Experimental study on the metabolism of triethylamine in man. Br J Ind Med. 1988;45(4):262–268. 10.1136/oem.45.4.262 3378003
18 Åkesson B Vinge E Skerfving S Pharmacokinetics of triethylamine and triethylamine-N-oxide in man. Toxicol Appl Pharmacol. 1989;100(3):529–538. 10.1016/0041-008X(89)90300-1 2781570
19 Åkesson B Skerfving S Ståhlbom B Lundh T Metabolism of triethylamine in polyurethane foam manufacturing workers. Am J Ind Med. 1989;16(3):255–265. 10.1002/ajim.4700160304 2782314
20 Snyder R Nitrogen and phosphorus solvents. Vol. II. Amsterdam, Netherlands: Elsevier; 1990. (Ethyl Browning’s toxicity and metabolism of industrial solvents.).
21 Carpenter CP Smyth HF Jr Shaffer CB The acute toxicity of ethylene imine to small animals. J Ind Hyg Toxicol. 1948;30(1):2–6. 18895721
22 Brieger H Hodes WA Toxic effects of exposure to vapors of aliphatic amines. AMA Arch Ind Hyg Occup Med. 1951;3(3):287–291. 14810255
23 Tkachev PG [Hygienic assessment of the effect of inhalation of small concentrations of aliphatic ethylamines]. Gig Sanit. 1971;36(9):8–11. 5160206
24 Lynch DW Moorman WJ Lewis TR Stober P Hamlin RD Schueler RL Subchronic inhalation of triethylamine vapor in Fischer-344 rats: organ system toxicity. Toxicol Ind Health. 1990;6(3-4):403–414. 10.1177/074823379000600304 2237926
25 Proctor NH Hughes JP Chemical hazards of the workplace. Philadelphia (PA): J.B. Lippincott Co.; 1978.
26 Hoechst Celanese Corporation. Dermal corrosivity study in rabbits with C-01043 triethylamine (IMO) with attachments and cover letter dated 021390. 1989. U.S. Environmental Protection Agency/OTS Public Files, Doc. No. 86-000000098, Fiche No. 0522354.
27 Union Carbide Corporation. Initial submission: Primary dermal irritation study of ethylamine, triethylamine, and diethylamine in albino rabbits with cover letter dated 072892. 1986. U.S. Environmental Protection Agency/OTS Public Files, Document No. 86-870001409, Fiche No. 0515571.
28 Pennwalt Corporation. Eye irritancy in rabbits using triethylamine (final report). 1986. U.S. Environmental Protection Agency/OTS Public Files, Doc. No. 86-870000535, Fiche No. 0513613.
29 Virginia Chemicals. Acute dermal toxicity of triethylamine in rabbits. 1987. U.S. Environmental Protection Agency/OTS Public Files, Document No. 86-870000815, Fiche No. OTS0515253.
30 Union Carbide Corporation. Range finding tests on triethylamine. 1949. U.S. Environmental Protection Agency/OTS Public Files, Document No. 86-870001409, Fiche No. 0515571.
31 Union Carbide Corporation. Range finding toxicity studies of triethylamine. 1979. U.S. Environmental Protection Agency/OTS Public Files, Document No. 86-870001448, Fiche No. 0515610.
32 Åkesson B Bengtsson M Florén I Visual disturbances after industrial triethylamine exposure. Int Arch Occup Environ Health. 1986;57(4):297–302. 10.1007/BF00406184 3710602
33 Kesson BA Florén I Skerfving S Visual disturbances after experimental human exposure to triethylamine. Br J Ind Med. 1985;42(12):848–850. 10.1136/oem.42.12.848 4074656
34 Mellerio J Weale RA Hazy vision in amine plant operatives. Br J Ind Med. 1966;23(2):153–154. 5929690
35 Reilly MJ Rosenman KD Abrams JH Zhu Z Tseng C Hertzberg V Rice C Ocular effects of exposure to triethylamine in the sand core cold box of a foundry. Occup Environ Med. 1995;52(5):337–343. 10.1136/oem.52.5.337 7795757
36 Ashland Chemical Company. Monitoring surveys: N,n-diethylethanamine, isopropanol, butanol, methanol, acetone, hexane and toluene. 1986. U.S. Environmental Protection Agency/OTS Public Files, Document No. 86 870001686, Fiche No., 0515762.
37 Hansen ES Cancer mortality among Danish molders. Am J Ind Med. 1991;20(3):401–409. 10.1002/ajim.4700200312 1928115
38 Schweinsberg F Sander J [Cancerogenic nitrosamines consisting of simple aliphatic tertiary amines and nitrite]. Hoppe Seylers Z Physiol Chem. 1972;353(11):1671–1676. 10.1515/bchm2.1972.353.2.1671 4648295
39 Zeiger E, Anderson B, Haworth S, Lawlor T, Mortelmans K, Speck W. Salmonella mutagenicity tests: III. Results from the testing of 255 chemicals. Environ Mutagen. 1987; 9(S9):61-109.
40 Lindegård B Mathiasson L Jönsson JÅ Åkesson B Controlled thermal degradation for the identification and quantification of amine N-oxides in urine. J Chromatogr A. 1990;514(2):293–304. 10.1016/S0021-9673(01)89401-2 2258398
41 Gorgacz EJ. Occupational cardiac toxicity – acute diethylamine exposures. Cincinnati, OH: National Institute for Occupational Safety and Health; 1987. NIOSH Study No. CAN 339.
42 Schueler RL. Report of pathologic findings in Fischer 344 rats exposed by inhalation to allylamine, ethylamine, diethylamine, and triethylamine. Unpublished report prepared by Research Pathology Associates, Inc., for Dr. David Groth. National Institute of Occupational Safety and Health; 1984. NIOSH Contract No. 211-83-0020.
43 Brecher G, Schneiderman M. A time-saving device for the counting of reticulocytes. Am J Clin Pathol. 1950; 20(11_ts):1079-1083. 10.1093/ajcp/20.11_ts.1079 10.1093/ajcp/20.11_ts.1079
44 Maronpot RR Boorman GA Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982;10(2):71–78. 10.1177/019262338201000210 28094716
45 Boorman GA Montgomery CA Jr Eustis SL Wolfe MJ McConnell EE Hardisty JF Quality assurance in pathology for rodent carcinogenicity studies. In: Milman HA Weisburger EKeditors. Handbook of Carcinogen Testing Park Ridge. NJ: Noyes Publications; 1985. p. 345–357.
46 Gart JJ Chu KC Tarone RE Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979;62(4):957–974. 285297
47 Dunnett CW A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955;50(272):1096–1121. 10.1080/01621459.1955.10501294
48 Williams DA A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971;27(1):103–117. 10.2307/2528930 5547548
49 Williams DA The comparison of several dose levels with a zero dose control. Biometrics. 1972;28(2):519–531. 10.2307/2556164 5037867
50 Shirley E A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977;33(2):386–389. 10.2307/2529789 884197
51 Williams DA A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986;42(1):183–186. 10.2307/2531254 3719054
52 Dunn OJ Multiple comparisons using rank sums. Technometrics. 1964;6(3):241–252. 10.1080/00401706.1964.10490181
53 Jonckheere AR A distribution-free k-sample test against ordered alternatives. Biometrika. 1954;41(1/2):133–145. 10.2307/2333011
54 Dixon W Massey F Introduction to statistical analysis. New York (NY): McGraw Hill Book Company Inc; 1957. 10.2307/2332898
55 Girard DM Sager DB The use of Markov chains to detect subtle variation in reproductive cycling. Biometrics. 1987;43(1):225–234. 10.2307/2531963 3567307
56 Code of Federal Regulations (CFR). 21:Part 58.
57 MacGregor JT Wehr CM Henika PR Shelby MD The in vivo erythrocyte micronucleus test: measurement at steady state increases assay efficiency and permits integration with toxicity studies. Fundam Appl Toxicol. 1990;14(3):513–522. 10.1016/0272-0590(90)90255-I 2111256
58 Jiang XZ Buckley LA Morgan KT Pathology of toxic responses to the RD50 concentration of chlorine gas in the nasal passages of rats and mice. Toxicol Appl Pharmacol. 1983;71(2):225–236. 10.1016/0041-008X(83)90339-3 6636187
59 Broderson JR Lindsey JR Crawford JE The role of environmental ammonia in respiratory mycoplasmosis of rats. Am J Pathol. 1976;85(1):115–130. 970435
60 Kruysse A Feron VJ Til HP Repeated exposure to acetaldehyde vapor. Studies in Syrian golden hamsters. Arch Environ Health. 1975;30(9):449–452. 10.1080/00039896.1975.10666748 1164047
61 Feron VJ Kruysse A Til HP Immel HR Repeated exposure to acrolein vapour: subacute studies in hamsters, rats and rabbits. Toxicology. 1978;9(1-2):47–57. 10.1016/0300-483X(78)90030-6 653741
62 Beard R Noe J Aromatic nitro and amino compounds. In: Clayton G Clayton Reditors. Patty’s Industrial Hygiene and Toxicology. 3rd ed. New York (NY): John Wiley and Sons; 1981. p. 213–2489.
63 Buckley LA Morgan KT Swenberg JA James RA Hamm TE Jr Barrow CS The toxicity of dimethylamine in F-344 rats and B6C3F1 mice following a 1-year inhalation exposure. Fundam Appl Toxicol. 1985;5(2):341–352. 10.1016/0272-0590(85)90082-X 3988003
64 Gross EA Patterson DL Morgan KT Effects of acute and chronic dimethylamine exposure on the nasal mucociliary apparatus of F-344 rats. Toxicol Appl Pharmacol. 1987;90(3):359–376. 10.1016/0041-008X(87)90129-3 3660407
65 Steinhagen WH Swenberg JA Barrow CS Acute inhalation toxicity and sensory irritation of dimethylamine. Am Ind Hyg Assoc J. 1982;43(6):411–417. 10.1080/15298668291409956 7113921
66 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of diethylamine (CASRN 109 89-7) in F344/N rats and B6C3F1 mice (inhalation studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2012. Technical Report Series No. 566. NIH Publication No. 12-5908.
67 Long PH Leininger JR Nold JB Lieuallen WG Guides for Toxicologic Pathology. Washington (DC): STP/ARP/AFIP; 1993. Proliferative lesions of bone, cartilage, tooth, and synovium in rats.
68 National Toxicology Program (NTP). Toxicology and Carcinogenesis Studies of 1,2-Epoxybutane (CASRN 106 88-7) in F344/N Rats and B6C3F1 Mice (Inhalation Studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1988. Technical Report Series No. 329. NIH Publication No. 88-2585.
69 National Toxicology Program (NTP). Toxicology and carcinogenesis studies of C.I. pigment red 3 (CASRN 2425 85-6) in F344/N rats and B6C3F1 mice (feed studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 1992. Technical Report Series No. 407. NIH Publication No. 92-3138.
70 Union Carbide Corporation. Amine-induced blue-gray vision: Brief review. Danbury, CT; 1984.
71 Albrecht WN Stephenson RL Health hazards of tertiary amine catalysts. Scand J Work Environ Health. 1988;14(4):209–219. 10.5271/sjweh.1930 3051334
72 Dernehl CU Health hazards associated with polyurethane foams. J Occup Med. 1966;8(2):59–62. 5903304
73 Järvinen P Engström K Riihimäki V Ruusuvaara P Setälä K Effects of experimental exposure to triethylamine on vision and the eye. Occup Environ Med. 1999;56(1):1–5. 10.1136/oem.56.1.1 10341738
74 Potts AM Rouse EF Eiferman RA Au PC An unusual type of keratopathy observed in polyurethane workers and its reproduction in experimental animals. Am J Ind Med. 1986;9(2):203–213. 10.1002/ajim.4700090211 3963001
75 Wagoner MD Chemical injuries of the eye: current concepts in pathophysiology and therapy. Surv Ophthalmol. 1997;41(4):275–313. 10.1016/S0039-6257(96)00007-0 9104767
76 Paterson CA Pfister RR Intraocular pressure changes after alkali burns. Arch Ophthalmol. 1974;91(3):211–218. 10.1001/archopht.1974.03900060219014 4814971
77 Paterson CA Pfister RR Levinson RA Aqueous humor pH changes after experimental alkali burns. Am J Ophthalmol. 1975;79(3):414–419. 10.1016/0002-9394(75)90614-5 235843
78 Pouchert CJ The Aldrich library of infrared spectra. Pouchert CJeditor. Milwaukee (WI): Aldrich Chemical Company Inc.; 1981.
79 Pouchert CJ The Aldrich library of FT-IR spectra. Milwaukee (WI): Aldrich Chemical Company Inc.; 1997.