# Discussion

Triethylamine is a highly alkaline and corrosive aliphatic amine with widespread occupational use. Because it has a relatively high vapor pressure, inhalation exposure to triethylamine vapors is an occupational hazard in industries where it is used. Triethylamine is a direct-acting contact irritant, and exposure to its vapors can cause irritation to the eyes and the mucous membranes lining the respiratory tract. Exposure of workers to triethylamine vapors results primarily in irritation of the eyes at concentrations greater than 5 ppm and irritation of the nose and throat at higher concentrations (greater than 15 ppm) resulting in coughing and wheezing.^8^ Although respiratory distress can occur in situations of extreme exposure,^36^ acute occupational exposures to triethylamine are usually self-limiting because the severe irritation to the eyes, nose, and throat results in workers being removed from exposure.

The target sites for triethylamine vapors are similar in humans and rodents; however, because rodents are obligate nose breathers the nasal cavity is often more severely affected than in humans. The nasal cavity is the primary target site for rodents exposed to many direct-acting, reactive, gaseous chemicals such as chlorine,^58^ formaldehyde, ammonia,^59^ acetaldehyde,^60^ and acrolein.^61^ In addition to the nasal irritation, aliphatic amines also have been reported to cause tracheitis, bronchitis, pneumonitis and pulmonary edema.^62-65^

In the current studies, triethylamine toxicity was primarily restricted to the nose and eye. Species and gender differences in susceptibility to triethylamine were minor. In 2-week studies, triethylamine was lethal for rats and mice exposed to concentrations of 800 or 1,000 ppm. Marked necrosis of the olfactory epithelium of the nose in rats and bronchial necrosis and corneal degeneration (vacuolation) and necrosis in both rats and mice were present in animals that died early. These lesions in the nose and bronchi were not observed in surviving rats exposed to 400 ppm or less, although corneal lesions of lesser severity were noted in a few 400 ppm females and a few 200 and 100 ppm male and female rats. Nasal lesions were exposure concentration-related in surviving animals and were most severe in rats and mice exposed to 400 ppm. The observed decreases in body weights may have been related to a reduced feed intake associated with triethylamine effects on olfaction.

Exposure to 400 ppm triethylamine for 2 weeks caused necrosis of turbinate bone, squamous metaplasia of respiratory epithelium, and atrophy of olfactory epithelium. At 400 ppm, lesions also extended to the lower airways with bronchial degeneration and suppurative inflammation in rats and chronic active inflammation of the bronchi in mice. Exposure to 200 ppm produced less severe bronchial and nasal lesions than produced by 400 ppm, and at 100 ppm there were no lung lesions and nasal lesions were minimal except for mild olfactory epithelial atrophy in mice. Similar types of nasal lesions (turbinate necrosis, squamous metaplasia, and olfactory atrophy) in rats and mice were observed after exposure for 2 weeks to the structurally related aliphatic amine, diethylamine.^66^

In the 3-month studies, nasal lesions in rats consisted primarily of respiratory epithelial hyperplasia and olfactory epithelial atrophy, and the severity of nasal lesions increased with increasing exposure concentration. On the other hand, nasoturbinate necrosis was present in all male and female mice exposed to 200 ppm triethylamine and turbinate atrophy was present in several of these 200 ppm mice. In addition, hyperostosis (osteopetrosis) of the turbinates was present in almost all mice exposed for 3 months, and the severity increased with increasing triethylamine concentration. Hyperostosis of the nasal turbinates is an uncommon nonneoplastic thickening of the naso- and maxilloturbinate bones. Mechanisms of hyperostosis may be divided into proliferative and nonproliferative categories, based upon evidence of either increased bone cell proliferation or decreased bone resorption, respectively.^67^ This lesion has been reported in 15 (including the current study) of over 500 NTP studies. Most of these 15 studies were 2-year studies, and the incidences of hyperostosis were low and not dose related. In only four of these 15 studies did there appear to be a significant association with treatment; three of these were inhalation studies (triethylamine, diethylamine, and 1,2-epoxybutane), and one was a chronic feed study (C.I. Pigment Red 3).^68,69,66^ The triethylamine (3-month) and diethylamine (2-year) studies were unique in that all of the mice exposed to the highest concentrations exhibited the lesion, whereas only low incidences were reported in the other studies. In addition, hyperostosis of the turbinates was observed in only a few rats in the 2-year diethylamine study and none in the 3-month triethylamine study, suggesting a species difference in susceptibility.

Corneal irritation and edema have been documented in workers exposed to triethylamine concentrations as low as 4 to 6 ppm.^32^ In the current 2-week rat study, the no-observed-effect level (NOEL) for ocular lesions was less than 100 ppm. These lesions consisted of corneal degeneration (vacuolation), corneal necrosis, and cataracts in both rats and mice exposed to the higher exposure concentrations. With the reduced exposure concentrations used in the 3-month studies, ocular lesions were less severe in the rats and absent in the mice. Because triethylamine reacts directly with the corneal epithelium, it is unlikely that rodents are more resistant than humans to these ocular effects, but rather the animals were able to limit ocular exposure by closing their eyes during the 6-hour exposures. These exposures also took place during daytime when rodents are not normally awake and active. The visual disturbances reported by workers are the earliest and most sensitive markers of triethylamine exposure. Visual disturbances included irritation, blurred vision, glaucopsia (blue-gray vision), and halo vision. Although these changes may also occur in rodents, detection of these markers is not clinically possible.

The mechanism(s) by which triethylamine and other amines cause visual disturbances is unknown. It has been suggested that edema and increased corneal thickness may cause light scattering resulting in the reported visual effects.^34,70^ Mellerio and Weale^34^ also proposed that glaucopsia may be related to the Tyndall effect caused by denaturation of proteins in the corneal epithelium. Corneal edema and mydriasis with cycloplegia have also been proposed as major reasons for the visual disturbances caused by amines.^71^ Halo vision reported by exposed workers may result from diffraction of light into spectral colors by droplets of fluid in the corneal epithelia.^70^ Examination of corneas of workers exposed to aliphatic amines under slit-lamp microscopy revealed a diffuse edema with numerous small vesicular collections of fluid within the corneal stroma.^72^ As noted in the Results section of the current Toxicity Study Report, microvacuolation of the corneal epithelium was seen in many of the rats and mice in the high exposure concentration groups in the 2-week studies. The subepithelial vesicles of the cornea that were present in some of the exposed male and female rats in the current study are probably similar to the subepithelial microcysts reported by Järvinen et al.^73^ and the subepithelial vesicles described by Potts et al.^74^ and Dernehl^72^ in humans exposed to triethylamine.

Inhaled triethylamine is readily absorbed from the lungs and can be detected in urine and plasma in humans^19,18^ suggesting that pulmonary absorption and systemic exposure to triethylamine can also occur in exposed rats and mice. While systemic exposure may have occurred in the current study, there was little evidence of systemic toxicity. Some organ weights of rats and mice were significantly different from those of the chamber controls, suggesting potential systemic toxicity. The lower absolute organ weights and higher relative organ weights were attributed to significantly lower body weights.

The high urinary excretion of triethylamine in exposed humans^17^ and the significantly higher relative kidney weights of male and female rats in the 2-week and 3-month studies suggested potential systemic exposure-related nephrotoxicity. Similarly, relative kidney weights in male and female rats exposed for 3 months to the structurally related aliphatic amine, diethylamine, were greater than those of the chamber controls.^66^ However, in both the current study and the diethylamine study, higher relative kidney weights were not associated with histopathologic lesions or chemical-related effects on clinical pathology indices. Although mild kidney toxicity due to systemic exposure cannot be ruled out, the lack of histopathologic evidence and lower absolute kidney weights suggest that these effects were related to the significantly lower body weights. Importantly, exposure of rats and mice to diethylamine for 2 years did not result in kidney toxicity.^66^

Retinal degeneration was observed in a few exposed rats in the 3-month study of triethylamine. Unlike the cornea, the retina is not directly exposed to triethylamine vapor, suggesting potential exposure via the blood. However, it is more likely that retinal effects were caused by triethylamine absorbed from the ocular surface. Alkaline chemicals such as triethylamine are known to readily penetrate into the eye. The absorbed alkali can damage the cornea as well as other anterior segment structures^75^ and cause a rapid rise in intraocular pressure and in the anterior chamber pH,^76,77^ all of which could contribute to the retinal degeneration. It is also possible that the low incidences of retinal degeneration were not exposure related. Although retinal changes were not present in chamber control rats, the incidences in exposed groups were not concentration related or statistically significant. Chronic exposure of rats and mice to the related compound, diethylamine, did not result in exposure-related retinal changes.

Also suggestive of a potential systemic effect was the decreased sperm motility in rats exposed to 50, 100, or 200 ppm triethylamine for 3 months. Although these changes were small in magnitude (3% to 6% lower than chamber control values), they were exposure concentration related and statistically significant. These rats also displayed lower total number of sperm/cauda (4% to 9%) and concomitant significant increases in the number of spermatid/mg testis at the 100 and 200 ppm exposure concentrations. Taken together, these data are suggestive of a potential effect on sperm transit from the testis to the epididymis; however, this apparent effect was small in magnitude. Male mice exposed to 200 ppm triethylamine for 3 months exhibited lower epididymis and testis weights (10% and 5%, respectively) compared to the chamber controls. A concentration-related decrease in sperm motility was also reported for male rats and mice exposed for 3 months to the related chemical, diethylamine.^66^ There was no histopathologic evidence of testicular toxicity in rats or mice exposed to either triethylamine or diethylamine for 3 months, or in rats or mice exposed to diethylamine for 2 years. However, the effects noted above on the sperm parameters and the reproductive organ weights suggest that triethylamine exhibits the potential to be a reproductive toxicant in male F344/N rats and B6C3F1/N mice.

Chronic studies of triethylamine were not conducted because subchronic toxicity was similar to that of diethylamine, a closely related aliphatic amine that was previously selected for evaluation of carcinogenicity.

Under the conditions of the 3-month inhalation studies, there were treatment-related lesions in male and female rats and mice. The major targets of triethylamine exposure in rats and mice included the nose and eyes. In rats, the most sensitive measure of triethylamine exposure was respiratory epithelium hyperplasia of the nasal cavity with a lowest-observed-effect level (LOEL) of 12.5 ppm in males and females. In mice, the most sensitive measure of triethylamine exposure was turbinate hyperostosis of the nasal cavity with a LOEL of 12.5 ppm in males and females.