# Results

## Rats

### Two-week Study

Rats exposed to 800 or 1,000 ppm triethylamine died after the first exposure on day 1 (Table 2). Final mean body weights of all surviving exposed male rats and the 200 and 400 ppm female rats were significantly less than those of the chamber controls; mean body weight gains were significantly less in all surviving groups. In addition to ataxia and tremors that were observed initially on day 1, lethargy, abnormal breathing, and nasal discharge were observed throughout the study in the 400 ppm rats. Abnormal breathing was observed in all 400 ppm males and females at the end of the study. Nasal discharge (one male and one female) and lethargy (all male and female rats) were observed only on the first 2 days of exposure to 200 ppm.

Table 2 Survival and Body Weights of Rats in the Two-week Inhalation Study of Triethylamine^a^

Concentration (ppm) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 5/5 | 102 ± 2 | 170 ± 4 | 68 ± 3
100 | 5/5 | 100 ± 3 | 159 ± 4* | 59 ± 2* | 94
200 | 5/5 | 102 ± 2 | 152 ± 3** | 49 ± 2** | 89
400 | 5/5 | 101 ± 2 | 120 ± 3** | 19 ± 2** | 70
800 | 0/5^c^ | 102 ± 2 | – | – | –
1,000 | 0/5^c^ | 101 ± 3 | – | – | –
Female
0 | 5/5 | 89 ± 2 | 128 ± 2 | 39 ± 1
100 | 5/5 | 91 ± 1 | 125 ± 2 | 35 ± 1* | 98
200 | 5/5 | 89 ± 2 | 117 ± 3** | 28 ± 2** | 91
400 | 5/5 | 89 ± 2 | 103 ± 3** | 14 ± 2** | 80
800 | 0/5^c^ | 89 ± 1 | – | – | –
1,000 | 0/5^c^ | 87 ± 2 | – | – | –

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ test.

** P ≤ 0.01.

^a^ Weights and weight changes are given as mean ± standard error. Subsequent calculations are based on animals surviving to the end of the study.

^b^ Number of animals surviving at 16 days/number initially in group.

^c^ Day of deaths: 1.

The absolute and relative kidney weights of 100 ppm females and the relative kidney weights of 200 and 400 ppm males and females were significantly greater than those of the chamber controls (Table D-1). Because there was no histopathologic evidence of kidney toxicity at any concentration, the higher relative kidney weights were considered secondary to the significantly lower body weights (30% in males, 20% in females). Absolute weights of the heart and liver in all surviving male exposed groups were significantly lower than those of the chamber controls. The absolute and relative right testis and thymus weights and absolute right kidney weight of 400 ppm males and the absolute and relative thymus weights of 400 ppm females were also significantly lower than those of the chamber controls. Lower absolute organ weights were considered to be secondary to decreased body weights.

At necropsy, gastric dilatation due to forced mouth breathing was observed in rats that died early and a few rats had lung lesions. Gastric dilatation is commonly observed in animals with nasal toxicity resulting in occluded or partially occluded nasal airflow.

All 800 and 1,000 ppm rats died early and had marked necrosis of the respiratory and olfactory epithelium of the nose and the bronchial epithelium of the lung, as well as corneal epithelial vacuolation and sometimes corneal necrosis (Table 3).

Table 3 Incidences of Selected Nonneoplastic Lesions in Rats in the Two-week Inhalation Study of Triethylamine

| Chamber Control | 100 ppm | 200 ppm | 400 ppm | 800 ppm | 1,000 ppm
Male
Nose^a^ | 5 | 5 | 5 | 5 | 5 | 5
Inflammation, Suppurative^b^ | 0 | 1 (1.0)^c^ | 4* (1.3) | 5** (3.0) | 0 | 0
Olfactory Epithelium, Atrophy | 0 | 3 (1.0) | 4* (1.0) | 3 (1.7) | 0 | 0
Olfactory Epithelium, Respiratory Epithelium Necrosis | 0 | 0 | 0 | 0 | 5** (4.0) | 5** (4.0)
Respiratory Epithelium, Hyperplasia | 0 | 4* (1.0) | 5** (1.2) | 5** (1.6) | 0 | 0
Respiratory Epithelium, Metaplasia, Squamous | 0 | 0 | 2 (1.0) | 5** (2.0) | 0 | 0
Respiratory Epithelium, Ulcer | 0 | 0 | 0 | 5** (3.2) | 0 | 0
Turbinate, Necrosis | 0 | 0 | 0 | 4* (3.0) | 0 | 0
Lung | 5 | 5 | 5 | 5 | 5 | 5
Bronchus, Degeneration | 0 | 0 | 4* (1.3) | 5** (2.6) | 0 | 0
Bronchus, Inflammation, Suppurative | 0 | 0 | 0 | 5** (2.2) | 0 | 0
Bronchus, Necrosis | 0 | 0 | 0 | 0 | 5** (4.0) | 5** (4.0)
Bronchus, Regeneration | 0 | 0 | 0 | 5** (3.4) | 0 | 0
Female
Nose | 5 | 5 | 5 | 5 | 5 | 5
Inflammation, Suppurative | 0 | 1 (1.0) | 1 (1.0) | 5** (3.4) | 0 | 0
Olfactory Epithelium, Atrophy | 0 | 2 (1.0) | 4* (1.0) | 3 (1.0) | 0 | 0
Olfactory Epithelium, Respiratory Epithelium, Necrosis | 0 | 0 | 0 | 0 | 5** (4.0) | 5** (4.0)
Respiratory Epithelium, Hyperplasia | 0 | 4* (1.0) | 4* (1.0) | 3 (1.0) | 0 | 0
Respiratory Epithelium, Metaplasia, Squamous | 0 | 0 | 0 | 5** (2.2) | 0 | 0
Respiratory Epithelium, Ulcer | 0 | 0 | 0 | 4* (2.5) | 0 | 0
Turbinate, Necrosis | 0 | 0 | 0 | 3 (3.0) | 0 | 0
Lung | 5 | 5 | 5 | 5 | 5 | 5
Bronchus, Degeneration | 0 | 0 | 4* (1.0) | 5** (2.8) | 0 | 0
Bronchus, Inflammation, Suppurative | 0 | 0 | 0 | 5** (2.0) | 0 | 0
Bronchus, Necrosis | 0 | 0 | 0 | 0 | 5** (4.0) | 5** (4.0)
Bronchus, Regeneration | 0 | 0 | 0 | 5** (2.8) | 0 | 0

* Significantly different (P ≤ 0.05) from the chamber control group by the Fisher exact test.

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

In the nose, there were significantly increased incidences of respiratory epithelium hyperplasia in all surviving groups of exposed males (Table 3); turbinate necrosis, squamous metaplasia of the respiratory epithelium, suppurative inflammation, and respiratory epithelium ulcer in 400 ppm males; and suppurative inflammation and olfactory epithelium atrophy in 200 ppm males. In 400 ppm females, there were significantly increased incidences of suppurative inflammation, squamous metaplasia of the respiratory epithelium, and respiratory epithelium ulcer. There were also significantly increased incidences of respiratory epithelium hyperplasia in 100 and 200 ppm females, and olfactory epithelium atrophy in 200 ppm females. In both sexes, the severities of these lesions were generally greater at 400 ppm than in the lower exposure concentration groups.

Microscopically, lesions in the nose occurred most frequently in nasal sections of Level I and to a lesser extent in the dorsal meatus of Level II. Minimal to marked multifocal ulcers of the respiratory epithelium were accompanied by minimal to marked suppurative inflammation, mild to moderate squamous metaplasia, and minimal to mild respiratory cell hyperplasia with moderate necrosis of the turbinate bone underlying ulcers in 400 ppm rats. Lesions were generally less severe in the 100 and 200 ppm groups. Ulcers of the respiratory epithelium were multiple and resulted from localized loss of the mucosal epithelium down to the lamina propria. These ulcers were accompanied by suppurative inflammation with accumulations of neutrophils in the lamina propria. There was replacement of some normal columnar cells by squamous cells. Often the adjacent respiratory epithelium was thickened and hypercellular. Necrosis of the lateral hooks of the nasoturbinates in Level I was characterized by thinning of the bone, irregular scalloped borders due to resorption, fragmentation, and absence of osteocytes and bone lining cells. Minimal to moderate olfactory epithelium atrophy was observed in the dorsal meatus of Level II in all surviving male and female groups. In olfactory epithelial atrophy, there was a loss of cilia, altered orientation of affected cells, and decreased numbers of epithelial cells that resulted in thinning of the normal pseudostratified columnar cells.

In the lung, there were significantly increased incidences of bronchus degeneration in 200 and 400 ppm males and females and suppurative inflammation and bronchus regeneration in 400 ppm groups (Table 3). The severity of bronchus degeneration was greatest in the 400 ppm groups. Microscopically, minimal to moderate bronchus degeneration consisted of a loss of cilia and flattening of the bronchial epithelium. Mild to marked bronchus regeneration consisted of piling up and rounding of the bronchial epithelial cells.

In the eye, vacuolation (microvacuolar degeneration) of the corneal epithelium was noted in the 800 and 1,000 ppm males and females (Table 4 and Figure 4). In addition, in four males and one female, the central corneal epithelium was absent, which appeared to be secondary to marked vacuolar degeneration of the basal layer cells resulting in detachment from the underlying stroma. Although the possibility that autolysis could have contributed to these changes cannot be completely excluded, the severity of the associated vacuolar degenerative changes and the foci of residual necrosis were considered by the Pathology Peer Review (PPR) panel to be more consistent with epithelial loss (ulcer) due to the chemical effect than to the autolysis. In addition, necrosis of the medial portion of the iris and degeneration of peripheral fibers of the lens (cataracts) were noted in some of the 800 and 1,000 ppm rats. In the rats exposed to 400 ppm or less, all changes in the eyes were much milder, and included subepithelial vesicles of the cornea in a few animals in the 100, 200, and 400 ppm groups, sometimes accompanied by scattered apoptotic or necrotic cells.

Table 4 Incidences of Nonneoplastic Lesions of the Eye in Rats in the Two-week Inhalation Study of Triethylamine

| Chamber Control | 100 ppm | 200 ppm | 400 ppm | 800 ppm | 1,000 ppm
Male
Number Examined Microscopically | 5 | 5 | 5 | 4 | 5 | 5
Cornea, Epithelium, Ulcer^a^ | 0 | 0 | 0 | 0 | 3 (2.3)^b^ | 4* (2.5)
Cornea, Epithelium, Vacuolation | 0 | 0 | 0 | 0 | 5** (3.6) | 5** (2.8)
Cornea, Necrosis | 0 | 0 | 1 (1.0) | 0 | 5** (1.6) | 4* (1.3)
Cornea, Vesicle, Subepithelial | 0 | 1 | 2 | 0 | 1 | 0
Iris, Necrosis | 0 | 0 | 0 | 0 | 2 (2.0) | 3 (1.7)
Lens, Cataract | 0 | 0 | 0 | 0 | 1 (1.0) | 2 (1.0)
Female
Number Examined Microscopically | 5 | 5 | 5 | 5 | 5 | 5
Cornea, Epithelium, Ulcer | 0 | 0 | 0 | 0 | 0 | 1 (3.0)
Cornea, Epithelium, Vacuolation | 0 | 0 | 0 | 0 | 4* (3.3) | 4* (2.8)
Cornea, Necrosis | 0 | 1 (1.0) | 1 (1.0) | 0 | 1 (3.0) | 1 (1.0)
Cornea, Vesicle, Subepithelial | 0 | 2 | 2 | 2 | 0 | 0
Iris, Necrosis | 0 | 0 | 0 | 0 | 1 (2.0) | 0
Lens, Cataract | 0 | 0 | 0 | 0 | 1 (2.0) | 1 (2.0)

* Significantly different (P ≤ 0.05) from the chamber control group by the Fisher exact test.

** P ≤ 0.01.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Figure 4

Corneal Epithelial Vacuolation and Necrosis in F344/N Rats and B6C3F1/N Mice Exposed to Triethylamine by Inhalation for up to Two Weeks (H&E)

A) Normal corneal epithelium (arrowhead) in a chamber control male rat. B) Normal corneal epithelium (arrowhead) in a chamber control female mouse. C) Microvacuolation of the corneal epithelium (arrows) in a female rat exposed to 1,000 ppm triethylamine for 1 day. D) Microvacuolation of the corneal epithelium (arrows) in a male mouse exposed to 1,000 ppm triethylamine for 11 days. E) Necrosis of the corneal epithelium in a male rat exposed to 1,000 ppm triethylamine for 1 day with karyolysis (arrow), scattered nuclear pyknosis (arrowheads), and detachment of the epithelium from the stroma (asterisk in the gap). F) Necrosis of the corneal epithelium in a female mouse exposed to 1,000 ppm triethylamine for 1 day with nuclear pyknosis (arrowhead) and karyolysis (arrow). Original objective magnification: 40× for all photos.

Exposure concentration selection rationale: Exposure to concentrations of 800 and 1,000 ppm resulted in decreased survival. Exposure to 400 ppm resulted in decreased body weights (20% to 30%), decreased organ weights, and moderate histopathologic changes in the nose of male and female rats. The effects on body weight and the nasal cavity were less severe in groups exposed to 200 ppm or less. Therefore, exposure concentrations of 0, 12.5, 25, 50, 100, and 200 ppm triethylamine were selected for the 3-month study.

### Three-month Study

All rats survived to the end of the study (Table 5). The final mean body weights and body weight gains of males and females exposed to 200 ppm were significantly less than those of the chamber controls (Table 5; Figure 2). Abnormal breathing and thinness were noted in one 100 ppm female; no other chemical-related clinical findings were observed.

Table 5 Survival and Body Weights of Rats in the Three-month Inhalation Study of Triethylamine^a^

Concentration (ppm) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 107 ± 4 | 347 ± 7 | 240 ± 6
12.5 | 10/10 | 107 ± 3 | 360 ± 8 | 253 ± 7 | 104
25 | 10/10 | 108 ± 3 | 343 ± 9 | 235 ± 7 | 99
50 | 10/10 | 109 ± 5 | 352 ± 8 | 243 ± 7 | 101
100 | 10/10 | 108 ± 4 | 338 ± 4 | 230 ± 5 | 97
200 | 10/10 | 107 ± 4 | 300 ± 5** | 193 ± 5** | 87
Female
0 | 10/10 | 91 ± 3 | 209 ± 4 | 117 ± 4
12.5 | 10/10 | 90 ± 3 | 211 ± 4 | 120 ± 4 | 101
25 | 10/10 | 91 ± 2 | 204 ± 3 | 113 ± 2 | 98
50 | 10/10 | 92 ± 3 | 207 ± 5 | 115 ± 4 | 99
100 | 10/10 | 91 ± 3 | 198 ± 5 | 107 ± 5 | 95
200 | 10/10 | 92 ± 2 | 181 ± 3** | 89 ± 3** | 87

** Significantly different (P ≤ 0.01) from the chamber control group by Williams’ test.

^a^ Weights and weight changes are given as mean ± standard error.

^b^ Number of animals surviving at 14 weeks/number initially in group.

Figure 2

Growth Curves for Rats Exposed to Triethylamine by Inhalation for Three Months

There were no changes in the hematology endpoints that would be considered toxicologically relevant to triethylamine exposure (Table C-1). At day 3 in male and female rats exposed to 25 ppm or greater, there appeared to be a transient decrease in white blood cell numbers involving lymphocytes and eosinophils, which generally disappeared by day 23. The relevance of this transient leukocyte response to the potential toxicity of triethylamine is questionable. There were small (<15%) decreases in albumin, globulin, and total protein concentrations in males and females exposed to 100 or 200 ppm. This decrease in protein occurred only at week 14 and may have been related to the lower mean body weights.

The absolute heart, liver, lung, and thymus weights of 200 ppm males and the absolute heart, liver, and thymus weights of 200 ppm females were significantly less than those of the chamber control groups (Table D-2). The changes were considered to be related to decreased body weights.

Slight decreases in epididymal sperm motility were observed in 50, 100, and 200 ppm males (3%, 4%, and 6%, respectively, compared to chamber controls) and slight increases (10%) in the number of spermatid heads per mg testis were observed in 100 and 200 ppm males (Table E-1). Although exposed female rats exhibited a slight tendency towards increased amounts of time spent in metestrus, the increases were not significant and the number of cycling females, number of females with irregular cycles, and the lengths and numbers of the estrous cycles were similar to those of the chamber controls (Table E-2 and Table E-3; Figure 2).

In the olfactory epithelium of the nose, there were significantly increased incidences of atrophy in males exposed to 50 ppm or greater and in females exposed to 25 ppm or greater (Table 6, Table A-1, and Table A-2). In the respiratory epithelium of the nose, there were significantly increased incidences of hyperplasia in males and females exposed to 25 ppm or greater. The severities of these nasal lesions generally increased with increasing exposure concentration.

Table 6 Incidences of Selected Nonneoplastic Lesions in Rats in the Three-month Inhalation Study of Triethylamine

| Chamber Control | 12.5 ppm | 25 ppm | 50 ppm | 100 ppm | 200 ppm
Male
Nose^a^ | 10 | 10 | 10 | 10 | 10 | 10
Olfactory Epithelium, Atrophy^b^ | 0 | 0 | 0 | 10** (1.6)^c^ | 10** (2.2) | 10** (2.6)
Respiratory Epithelium, Accumulation, Hyaline Droplet | 0 | 0 | 0 | 0 | 0 | 3 (1.0)
Respiratory Epithelium, Hyperplasia | 0 | 3 (1.0) | 9** (1.2) | 9** (1.2) | 10** (1.7) | 10** (2.7)
Lung | 10 | 10 | 10 | 10 | 10 | 10
Alveolus, Infiltration Cellular, Histiocyte | 4 (1.0) | 5 (1.0) | 3 (1.0) | 2 (1.0) | 6 (1.0) | 6 (1.0)
Female
Nose | 10 | 10 | 10 | 10 | 10 | 10
Olfactory Epithelium, Atrophy | 0 | 0 | 4* (1.0) | 10** (1.9) | 10** (2.5) | 10** (2.9)
Respiratory Epithelium, Hyperplasia | 0 | 3 (1.0) | 9** (1.1) | 10** (1.7) | 10** (2.4) | 10** (2.7)
Lung | 10 | 10 | 10 | 10 | 10 | 10
Alveolus, Infiltration Cellular, Histiocyte | 2 (1.0) | 1 (1.0) | 4 (1.0) | 4 (1.0) | 7* (1.0) | 7* (1.1)

* Significantly different (P ≤ 0.05) from the chamber control group by the Fisher exact test.

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Microscopically, olfactory epithelium atrophy was a minimal to moderate change affecting the dorsal meatus in nasal section Level II of the nose and in more severe cases the dorsal meatus and septum in Level III. This atrophy was characterized by varying degrees of loss of olfactory sensory neurons from the epithelium, and decreases in nerve bundles and Bowman’s glands in the lamina propria. The affected epithelium was hypocellular and reduced in height. Small, ovoid cavities surrounded by a single layer of cuboidal epithelial cells that appeared to be the ducts of Bowman’s glands were sometimes seen within the atrophic epithelium.

Respiratory epithelium hyperplasia was a minimal to moderate change affecting the tall columnar epithelium of the septum in Levels I and II and sometimes the turbinates in Level II as well as the cuboidal to low columnar epithelium on the lateral wall and turbinates in Level I. Hyperplasia was characterized by increased numbers of closely packed epithelial cells with crowded nuclei, which caused thickening of the epithelium and often appeared to form two or three layers rather than the single layer seen normally. Increased numbers of goblet cells were seen within the hyperplastic pseudostratified columnar epithelium and small ovoid cavities surrounded by a single layer of cuboidal epithelial cells that appeared to be the ducts of respiratory glands, were sometimes seen within the hyperplastic cuboidal epithelium on the turbinates and lateral walls.

Hyaline droplet accumulation of the respiratory epithelium was a minimal change in a few 200 ppm males that consisted of an intracytoplasmic accumulation of homogeneously eosinophilic, hyaline material within respiratory epithelial cells along the septum and on the turbinates in Level II (Table 5 and Table A-1).

In the lung, there were significantly increased incidences of histiocyte cellular infiltration of the alveolus in 100 and 200 ppm females (Table 5 and Table A-2). The histiocytic cellular infiltrates were minimal to mild and consisted of one to a few, small, focal, subpleural accumulations of large, clear histiocytes within alveolar spaces, often accompanied by thickening of the alveolar walls due to increased numbers of Type II alveolar epithelial cells and slight fibrous thickening of the adjacent pleura.

One 200 ppm female was observed clinically to have an eye abnormality and four males and six females exposed to 200 ppm exhibited corneal lesions histologically (Table 7, Table A-1, and Table A-2). Mineralization of the subepithelial corneal stroma was noted in three males and two females, and epithelial vacuolation of the microvacuolar type similar to that observed in the 2-week animals was seen in two of the 200 ppm males. Three of the 200 ppm females exhibited subepithelial vesicles, and one female showed focal corneal epithelial ulceration. One male and one female exhibited one or more apoptotic cells within the corneal epithelium (minimal corneal necrosis), and mild chronic inflammation was present within the corneal stroma of this female. One of the 100 ppm males showed minimal mineralization of the corneal stroma. These corneal lesions were interpreted as related either to direct chemical effect or to healing changes (such as the mineralization) secondary to chemical injury. Retinal degeneration was also noted in one 50 ppm male, one 25 ppm female, two 100 ppm females, and one 200 ppm female. The etiology of the retinal changes was not certain because retinal degeneration may occur spontaneously in rats, although none was identified in the chamber controls. In addition, the retinal degeneration in the two 100 ppm females was unusual in that the inner portion of the retina (the ganglion cell layer, the inner nuclear layer, and the plexiform layers) was atrophic in contrast to the usual atrophy seen in the outer nuclear and photoreceptor layers; both of these cases were unilateral and patchy. It is possible that retinal damage was caused by triethylamine or a metabolite delivered either directly through the cornea or possibly through the retinal blood supply, although there was limited evidence of systemic toxicity in other organs.

Table 7 Incidences of Nonneoplastic Lesions of the Eye in Rats in the Three-month Inhalation Study of Triethylamine

| Chamber Control | 12.5 ppm | 25 ppm | 50 ppm | 100 ppm | 200 ppm
Male
Number Examined Microscopically | 9 | 10 | 10 | 10 | 10 | 10
Cornea, Mineralization^a^ | 0 | 0 | 0 | 0 | 1 (1.0)^b^ | 3 (1.3)
Cornea, Necrosis | 0 | 0 | 0 | 0 | 0 | 1 (1.0)
Cornea, Epithelium, Vacuolation | 0 | 0 | 0 | 0 | 0 | 2 (1.0)
Retina, Degeneration | 0 | 0 | 0 | 1 (2.0) | 0 | 0
Female
Number Examined Microscopically | 10 | 10 | 10 | 10 | 10 | 10
Anterior Chamber, Infiltration Cellular, Macrophage | 0 | 0 | 0 | 0 | 0 | 1 (1.0)
Cornea, Edema | 0 | 0 | 0 | 0 | 0 | 1 (2.0)
Cornea, Inflammation, Chronic | 0 | 0 | 0 | 0 | 0 | 1 (2.0)
Cornea, Mineralization | 0 | 2 | 0 | 0 | 0 | 2 (1.0)
Cornea, Necrosis | 0 | 0 | 0 | 0 | 0 | 1 (1.0)
Cornea, Vesicle, Subepithelial | 0 | 0 | 0 | 0 | 0 | 3
Cornea, Epithelium, Ulcer | 0 | 0 | 0 | 0 | 0 | 1 (1.0)
Lens, Cataract | 0 | 0 | 0 | 0 | 0 | 1 (1.0)
Retina, Degeneration | 0 | 0 | 1 (1.0) | 0 | 2 (2.0) | 1 (2.0)
Retina, Dysplasia | 0 | 0 | 0 | 0 | 0 | 1 (2.0)

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

## Mice

### Two-week Study

Three males and all females exposed to 1,000 ppm and three females exposed to 800 ppm died after the first exposure on day 1 (Table 8). In the remaining 1,000 ppm males, one animal died on day 3 and one died on day 11. In the 800 ppm males, one died on day 2, two died on day 3, and two died on day 11. The remaining 800 ppm females died on day 8. Mice exposed to 400 ppm lost weight during the study, and final mean body weights of these mice were significantly less than those of the chamber controls; mean body weight gains of 200 and 400 ppm mice were also significantly less. Lethargy, abnormal breathing, ataxia, tremor, and thinness were observed in all 400 ppm mice; these findings were also observed in the groups that died early. At the end of the study, all 400 ppm male and female rats were observed to be thin and to have abnormal breathing. Clinical signs were not observed in mice exposed to lower concentrations.

Table 8 Survival and Body Weights of Mice in the Two-week Inhalation Study of Triethylamine^a^

Concentration (ppm) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 5/5 | 22.8 ± 0.5 | 26.2 ± 0.6 | 3.5 ± 0.3
100 | 5/5 | 22.4 ± 0.4 | 25.6 ± 0.6 | 3.2 ± 0.3 | 97
200 | 5/5 | 22.7 ± 0.5 | 24.7 ± 0.5 | 2.0 ± 0.3** | 94
400 | 5/5 | 22.8 ± 0.4 | 19.4 ± 0.6** | −3.4 ± 0.4** | 74
800 | 0/5^c^ | 22.6 ± 0.5 | – | – | –
1,000 | 0/5^d^ | 22.5 ± 0.4 | – | – | –
Female
0 | 5/5 | 19.6 ± 0.3 | 22.7 ± 0.4 | 3.2 ± 0.5
100 | 5/5 | 19.7 ± 0.5 | 22.9 ± 0.4 | 3.2 ± 0.2 | 99
200 | 5/5 | 20.0 ± 0.5 | 21.8 ± 0.5 | 1.8 ± 0.4* | 96
400 | 5/5 | 20.0 ± 0.3 | 17.1 ± 0.3** | −2.9 ± 0.4** | 75
800 | 0/5^e^ | 20.2 ± 0.5 | – | – | –
1,000 | 0/5^f^ | 19.6 ± 0.2 | – | – | –

* Significantly different (P ≤ 0.05) from the chamber control group by Williams’ test.

** P ≤ 0.01.

^a^ Weights and weight changes are given as mean ± standard error. Subsequent calculations are based on animals surviving to the end of the study.

^b^ Number of animals surviving at 17 days/number initially in group.

^c^ Days of death: 2, 3, 3, 11, 11.

^d^ Days of death: 1, 1, 1, 3, 11.

^e^ Days of death: 1, 1, 1, 8, 8.

^f^ Day of deaths: 1.

The absolute liver weights and the absolute and relative thymus weights of 200 and 400 ppm males were significantly less than those of the chamber controls (Table D-3). The absolute and relative liver and thymus weights and the absolute right kidney weight in 400 ppm females were significantly lower than those of the chamber controls. Absolute heart weights in 400 ppm males and females were significantly lower than those of the chamber controls. Absolute organ weight changes were considered to be secondary to body weight changes. Relative organ weight changes in the 400 ppm males and females may also have been associated with the 25% decrease in mean body weights.

In the nose, turbinate necrosis occurred in all exposed groups of mice except for the 100 ppm groups and the severity increased with increased exposure concentration (Table 9). There were significantly increased incidences of olfactory epithelium atrophy in all surviving groups of exposed mice. There were also significantly increased incidences of acute inflammation and squamous metaplasia of the respiratory epithelium in 200 and 400 ppm males and females, and a few incidences of septum cartilaginous regeneration adjacent to areas of septal necrosis in 400 ppm groups.

Table 9 Incidences of Selected Nonneoplastic Lesions in Mice in the Two-week Inhalation Study of Triethylamine

| Chamber Control | 100 ppm | 200 ppm | 400 ppm | 800 ppm | 1,000 ppm
Male
Nose^a^ | 5 | 5 | 5 | 5 | 5 | 5
Inflammation, Acute^b^ | 0 | 0 | 5** (2.0)^c^ | 5** (3.0) | 3 (3.3) | 0
Olfactory Epithelium, Atrophy | 0 | 5** (2.0) | 5** (2.0) | 5** (3.0) | 0 | 0
Respiratory Epithelium, Metaplasia, Squamous | 0 | 0 | 5** (1.8) | 5** (3.0) | 2 (1.5) | 0
Turbinate, Necrosis | 0 | 0 | 5** (1.8) | 5** (3.0) | 5** (4.0) | 5** (4.0)
Septum, Regeneration | 0 | 0 | 0 | 3 (1.3) | 0 | 0
Lung | 5 | 0 | 5 | 5 | 5 | 5
Bronchus, Inflammation, Chronic Active | 0 | – | 0 | 5** (2.2) | 0 | 0
Bronchus, Necrosis | 0 | – | 0 | 0 | 3 (2.7) | 3 (3.3)
Female
Nose | 5 | 5 | 5 | 5 | 5 | 5
Inflammation, Acute | 0 | 1 (1.0) | 5** (2.0) | 5** (3.0) | 2 (3.0) | 0
Olfactory Epithelium, Atrophy | 0 | 5** (2.0) | 5** (2.2) | 5** (2.8) | 0 | 0
Respiratory Epithelium, Metaplasia, Squamous | 0 | 0 | 5** (1.8) | 5** (3.0) | 1 (2.0) | 0
Turbinate, Necrosis | 0 | 0 | 5** (2.0) | 5** (3.4) | 5** (3.6) | 5** (4.0)
Septum, Regeneration | 0 | 0 | 0 | 3 (2.0) | 0 | 0
Lung | 5 | 5 | 5 | 5 | 5 | 5
Bronchus, Inflammation, Chronic Active | 0 | 0 | 1 (2.0) | 4* (2.5) | 0 | 0
Bronchus, Necrosis | 0 | 0 | 0 | 0 | 3 (2.7) | 4* (3.0)
Bronchus, Vacuolization Cytoplasmic | 0 | 0 | 0 | 0 | 4* (2.5) | 2 (3.0)

* Significantly different (P ≤ 0.05) from the chamber control group by the Fisher exact test.

** P ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Microscopically, minimal to marked turbinate necrosis was characterized by partial to complete destruction of nasoturbinate hooks and maxilloturbinate dorsal tips, often associated with necrosis of the respiratory epithelium and lamina propria adjacent to the necrotic turbinate bone. The nasal septum cartilage was necrotic in Level I of some mice, often in association with zones of hyperplastic chondrocytes (cartilaginous regeneration) adjacent to the central necrotic cartilage. Minimal to marked acute inflammation was usually associated with areas of turbinate necrosis and was seen as collections of neutrophils in or on the nasal mucosa. Some mice had exudates (proteinaceous fluid and neutrophils) in the nasal airways. This inflammation was more prominent in mice that survived beyond day 3.

Minimal to moderate squamous metaplasia of the respiratory epithelium was seen on the septum, turbinates, and/or lateral walls in Levels I and II of the nose in many mice, as the epithelium regenerated and replaced the more vulnerable respiratory epithelium with one or more layers of low cuboidal or squamous cells. In some mice, soft tissue and bone underlying the squamous metaplasia was still necrotic, especially on turbinate tips. Squamous metaplasia was found in most mice exposed to 200 and 400 ppm as well as 800 ppm mice that lived to at least day 11.

Olfactory atrophy was mild or moderate in all mice exposed to 100, 200, or 400 ppm. Atrophy affected the olfactory epithelium lining the dorsal meatus in Level II, as well as the dorsal septum and adjacent turbinates in Level III. This atrophy was characterized by varying degrees of loss of olfactory sensory neurons from the epithelium, and decreased nerve bundles and Bowman’s glands in the lamina propria. The affected epithelium was hypocellular, reduced in height, and often resembled respiratory epithelium, consistent with “respiratory metaplasia.”

In the lung, there were incidences of focal necrosis of the mainstem bronchial epithelium in 800 and 1,000 ppm males and females and cytoplasmic vacuolization of the bronchial epithelium in many of the 800 and 1,000 ppm females (Table 9). There were significantly increased incidences of chronic active inflammation of the bronchi in 400 ppm males and females. The bronchial epithelium often exhibited regenerative changes that varied from squamous to columnar with one to multiple layers of cells with increased basophilia. The underlying lamina propria contained mononuclear inflammatory cells, fibroblasts, and occasional clusters of neutrophils.

In the eye of 800 and 1,000 ppm groups, there were increased incidences of corneal necrosis in males and significantly increased incidences of this lesion in females (Table 10). In many of these animals the corneal epithelium was partially absent. Although autolysis was often evident in the mice dying early, the absence of epithelium was interpreted as ulceration by the PPR because of the coexisting presence of necrotic debris on the surface, residual clusters of necrotic cells, and/or the vacuolar degenerative changes in the corneal epithelium of some animals (Figure 4). Peripheral degeneration of lens fibers (cataracts) was also noted in several 1,000 ppm males and females and in 800 ppm females.

Table 10 Incidences of Nonneoplastic Lesions of the Eye in Mice in the Two-week Inhalation Study of Triethylamine

| Chamber Control | 100 ppm | 200 ppm | 400 ppm | 800 ppm | 1,000 ppm
Male
Number Examined Microscopically | 5 | 5 | 5 | 5 | 5 | 5
Cornea, Epithelium, Ulcer^a^ | 0 | 0 | 0 | 0 | 2 (3.5)^b^ | 3 (3.3)
Cornea, Epithelium, Vacuolation | 0 | 0 | 0 | 0 | 3 (1.3) | 3 (1.3)
Cornea, Necrosis | 0 | 0 | 0 | 0 | 2 (2.0) | 3 (2.7)
Lens, Cataract | 0 | 0 | 0 | 0 | 0 | 3 (1.7)
Female
Number Examined Microscopically | 5 | 5 | 5 | 5 | 4 | 4
Cornea, Epithelium, Ulcer | 0 | 0 | 0 | 1 (1.0) | 3* (4.0) | 4** (3.5)
Cornea, Epithelium, Vacuolation | 0 | 0 | 0 | 0 | 0 | 1 (2.0)
Cornea, Necrosis | 0 | 0 | 0 | 0 | 3* (2.3) | 4** (2.8)
Lens, Cataract | 0 | 0 | 0 | 0 | 3* (2.0) | 4** (2.0)

* Significantly different (P ≤ 0.05) from the chamber control group by the Fisher exact test.

** P ≤ 0.01.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Exposure concentration selection rationale. Exposure to concentrations of 800 and 1,000 ppm resulted in decreased survival. Exposure to 400 ppm resulted in decreased body weights (approximately 25%), decreased organ weights, and moderate histopathologic changes in the nose of male and female mice. The effects on body weight and the nasal cavity were less severe in groups exposed to 200 ppm or less. Therefore, exposure concentrations of 0, 12.5, 25, 50, 100, and 200 ppm triethylamine were selected for the 3-month study.

### Three-month Study

All mice survived to the end of the study (Table 11). The final mean body weights and body weight gains of males and females exposed to 200 ppm were significantly less than those of the chamber controls (Table 11; Figure 3). No clinical findings related to triethylamine exposure were observed.

Table 11 Survival and Body Weights of Mice in the Three-month Inhalation Study of Triethylamine^a^

Concentration (ppm) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 22.9 ± 0.2 | 37.6 ± 0.8 | 14.7 ± 0.6
12.5 | 10/10 | 22.8 ± 0.3 | 38.3 ± 0.9 | 15.6 ± 0.7 | 102
25 | 10/10 | 22.3 ± 0.2 | 37.6 ± 0.7 | 15.2 ± 0.6 | 100
50 | 10/10 | 22.9 ± 0.3 | 38.6 ± 0.5 | 15.7 ± 0.5 | 103
100 | 10/10 | 23.0 ± 0.3 | 38.3 ± 0.6 | 15.3 ± 0.4 | 102
200 | 10/10 | 22.9 ± 0.3 | 31.9 ± 0.6** | 9.1 ± 0.6** | 85
Female
0 | 10/10 | 19.7 ± 0.3 | 32.8 ± 0.8 | 13.1 ± 0.8
12.5 | 10/10 | 19.8 ± 0.3 | 32.8 ± 0.9 | 13.1 ± 0.7 | 100
25 | 10/10 | 19.1 ± 0.3 | 31.4 ± 0.8 | 12.3 ± 0.8 | 96
50 | 10/10 | 20.1 ± 0.3 | 33.7 ± 0.5 | 13.7 ± 0.5 | 103
100 | 10/10 | 19.4 ± 0.3 | 33.0 ± 0.4 | 13.6 ± 0.4 | 101
200 | 10/10 | 19.4 ± 0.3 | 29.3 ± 0.5** | 9.9 ± 0.5** | 89

** Significantly different (P ≤ 0.01) from the chamber control group by Dunnett’s test.

^a^ Weights and weight changes are given as mean ± standard error.

^b^ Number of animals surviving at 14 weeks/number initially in group.

Figure 3

Growth Curves for Mice Exposed to Triethylamine by Inhalation for Three Months

There were no changes in the hematology endpoints that were attributable to inhalation of triethylamine (Table C-2).

The absolute and relative heart weights of 100 ppm females were significantly greater than those of the chamber controls (Table D-4). The lower absolute heart, right kidney, liver, and thymus weights of 200 ppm males and absolute liver weight of 200 ppm females were considered to be related to lower body weights.

No histopathologic changes were noted in the testes of male mice at 3 months. The weight of the left epididymis and testis in the 200 ppm group was significantly lower than that of the chamber control group (Table E-4). In females, there was an overall nonstatistically significant difference between the 200 ppm group and the chamber controls in the time spent in various stages of estrous (Table E-5 and Table E-6; Figure E-2).

In the nose, necrosis of the lateral hooks of the nasoturbinates was present in all 200 ppm males and females and was sometimes associated with ulceration of the overlying respiratory epithelium (Table 12, Table A-3, and Table A-4). Necrosis of bone was characterized by empty osteocyte lacunae, absence of lining cells (osteoblasts), attenuation and scalloping of the bone, fragmentation, and sometimes extrusion of the bone into the nasal cavity (Figure 5). Aggregates of neutrophils and bits of debris that may have been necrotic bone were seen at the ulcerated site, and hyperplasia of the epithelium bordering on the ulcer was sometimes present. Atrophy of the nastoturbinates was also noted in five males and three females exposed to 200 ppm.

Table 12 Incidences of Nonneoplastic Lesions of the Nose in Mice in the Three-month Inhalation Study of Triethylamine

| Chamber Control | 12.5 ppm | 25 ppm | 50 ppm | 100 ppm | 200 ppm
Male
Number examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Olfactory epithelium, atrophy^a^ | 0 | 0 | 0 | 9** (1.4)^b^ | 10** (3.0) | 10** (3.0)
Olfactory epithelium, accumulation, hyaline droplet | 0 | 0 | 0 | 1 (1.0) | 6** (1.2) | 0
Olfactory epithelium, vacuolization cytoplasmic | 0 | 0 | 0 | 6** (1.8) | 0 | 0
Respiratory epithelium, accumulation, hyaline droplet | 0 | 0 | 0 | 0 | 9** (1.7) | 0
Respiratory epithelium, metaplasia, squamous | 0 | 0 | 0 | 0 | 0 | 10** (1.1)
Turbinate, hyperostosis | 0 | 10** (1.0) | 9** (2.1) | 10** (2.6) | 10** (3.5) | 10** (3.8)
Turbinate, necrosis | 0 | 0 | 0 | 0 | 0 | 10** (2.6)
Turbinate, atrophy | 0 | 0 | 0 | 0 | 0 | 5* (2.0)
Female
Number examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Olfactory epithelium, atrophy | 0 | 0 | 0 | 10** (1.7) | 10** (2.8) | 10** (3.0)
Olfactory epithelium, accumulation, hyaline droplet | 0 | 0 | 0 | 7** (1.3) | 10** (2.7) | 8** (1.9)
Olfactory epithelium, vacuolization cytoplasmic | 0 | 0 | 0 | 5* (2.0) | 0 | 0
Respiratory epithelium, accumulation, hyaline droplet | 0 | 0 | 0 | 7** (1.9) | 10** (3.2) | 8** (2.4)
Respiratory epithelium, metaplasia, squamous | 0 | 0 | 0 | 0 | 0 | 9** (1.4)
Turbinate, hyperostosis | 0 | 8** (1.0) | 10** (1.6) | 10** (2.7) | 9** (3.2) | 10** (4.0)
Turbinate, necrosis | 0 | 0 | 0 | 0 | 0 | 10** (2.8)
Turbinate, atrophy | 0 | 0 | 0 | 0 | 0 | 3 (3.0)

* Significantly different (P ≤ 0.05) from the chamber control group by the Fisher exact test.

** P ≤ 0.01.

^a^ Number of animals with lesion.

^b^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Figure 5

Nasal Turbinate Hyperostosis and Necrosis in B6C3F1/N Mice Exposed to Triethylamine by Inhalation for Three Months (H&E)

A) Normal slender nasoturbinate bones (arrows) in a chamber control female mouse. B) Thickened (hyperostotic) nasoturbinates (arrows) in a female mouse exposed to 200 ppm triethylamine. Note that the nasal crest is also thickened (arrowhead) in this image taken at the same magnification as image A. C) Hyperostosis of the nasoturbinate in a female mouse exposed to 200 ppm triethylamine. Although there are many empty osteocyte lacunae (arrows) indicative of osteocyte necrosis, the osteoblasts rimming the bone (arrowhead) are viable and activated, and the bone is markedly thickened. D) Necrosis of the lateral hook of the nasoturbinate (arrow) in a female mouse exposed to 200 ppm triethylamine. The necrosis is characterized by the absence of both osteocytes and osteoblasts, attenuation of the bone, and extrusion of the distal end of the hook (arrowhead) into the nasal cavity accompanied by neutrophilic exudate. Original objective magnification: A = 4×, B = 4×, C = 20×, D = 20×.

In the olfactory epithelium, there were significantly increased incidences of olfactory epithelial atrophy in males and females exposed to 50 ppm or greater, hyaline droplet accumulation in females exposed to 50 ppm or greater and 100 ppm males, and cytoplasmic vacuolization in 50 ppm males and females (Table 12, Table A-3, and Table A-4). In the respiratory epithelium of the nose, there were significantly increased incidences of hyaline droplet accumulation in 100 ppm males and in females exposed to 50 ppm or greater, and significantly increased incidences of squamous metaplasia in 200 ppm males and females. In all exposed groups of males and females, the incidences of turbinate hyperostosis were significantly increased and were particularly prominent in the nasoturbinates. The severities of olfactory epithelium atrophy and turbinate hyperostosis in males and females increased with increasing exposure concentration.

Microscopically, olfactory epithelium atrophy consisted of a minimal to moderate loss of olfactory sensory neurons from the epithelium, accompanied by decreased nerve bundles and Bowman’s glands in the lamina propria. The affected epithelium was hypocellular and reduced in height, and sometimes was replaced by a ciliated, columnar respiratory-like epithelium. Minimal to mild lesions consisted of an increasing loss of sensory cells, nerve bundles, and Bowman’s glands in Level II. Moderate lesions involved the dorsal meatus of Level II, as well as the dorsal meatus, septum, and ethmoid turbinates in Level III. The atrophic epithelium in the dorsal meatus of Level II was sometimes replaced by a columnar respiratory-like epithelium.

Hyaline droplet accumulation in the olfactory epithelium consisted of an intracytoplasmic accumulation of homogeneously eosinophilic, hyaline material. It was minimal to mild in males and minimal to moderate in females. Similar changes affected the respiratory epithelium of both males and females. They were minimal to moderate in males and minimal to marked in females.

Cytoplasmic vacuolization of the olfactory epithelium was minimal to mild in males and minimal to moderate in females and consisted of multiple small to moderately large, round to ovoid, clear spaces scattered diffusely within the atrophic olfactory epithelium of the dorsal meatus in Level II.

Minimal to mild squamous metaplasia of the respiratory epithelium affected the cuboidal epithelium of the turbinates and lateral wall in Level I and was characterized by replacement of the normal cuboidal epithelium with one to three layers of flattened, squamous epithelial cells. The adjacent cuboidal epithelium in some of these animals was slightly thickened and hypercellular.

Hyperostosis of the nasal turbinates (Figure 5) was characterized by varying degrees of thickening of the nasal bones, particularly the naso- and maxilloturbinate bones, the nasal septum, and the skull overlying the nasal cavity. Normally the turbinate bones and skull consist of poorly cellular, layered, well-organized lamella bone. The affected bones were thickened by the deposition of cellular, disorganized woven bone, indicative of active bone formation or by bone with mixed woven and lamellar features. The thickened turbinates were characterized by numerous cement lines, which were often irregular and indicative of reversal cement lines, and the presence of numerous empty osteocyte lacunae. Lining cells (osteoblasts) were usually seen on the outer surface of the turbinates, but osteoclasts were seldom seen except occasionally in association with resorption of necrotic naso- or maxilloturbinate hooks. The severity of this change ranged from minimal to marked, with the average severity increasing with increasing dose. Minimal lesions consisted of slight thickening of the nasoturbinates and sometimes of the skull in Level I. Mild lesions consisted of fairly prominent thickening of the nasoturbinates usually with slight thickening of the tips of the maxilloturbinates and the skull in Level I. Moderate lesions consisted of prominent thickening of the naso- and maxilloturbinates and the skull in Level I. Marked lesions consisted of pronounced thickening of the naso- and maxilloturbinates and the skull in Level I, usually with obvious involvement of the bones in Level II as well.

## Genetic Toxicology

Triethylamine (100 to 10,000 µg/plate) was not mutagenic in Salmonella typhimurium strains TA98, TA100, TA1535, or TA1537 with or without hamster liver S9 activation enzymes (Table B-1; Zeiger et al.^39^)

A small, concentration-related increase in the frequency of micronucleated erythrocytes (biomarkers of chromosomal damage) was observed in peripheral blood of male mice in the 3-month study; the response, which was judged to be equivocal, was observed over the exposure concentration range of 12.5 to 200 ppm (Table B-2). No single exposed group was significantly elevated over the concurrent chamber control, but the trend test yielded a significant P value (0.006). No increase in micronucleated erythrocytes was seen in female mice. No significant changes in the percentage of polychromatic erythrocytes (immature erythrocytes) were noted in either male or female mice exposed to triethylamine, indicating an absence of bone marrow toxicity.