# Materials and Methods

## Procurement and Characterization of Triethylamine

Triethylamine was obtained from Alkyl Amines Chemicals, Limited (Maharashtra, India) in one lot (CE/04/01) that was used in the 2-week and 3-month studies. Identity and purity analyses were conducted by the analytical chemistry laboratories at Chemir/Polytech Laboratories, Inc. (Maryland Heights, MO), Galbraith Laboratories, Inc., (Knoxville, TN), and Research Triangle Institute (RTI) (Research Triangle Park, NC), and by the study laboratory at Battelle Toxicology Northwest (Richland, WA) (Appendix F). Reports on analyses performed in support of the triethylamine studies are on file at the National Institute of Environmental Health Sciences.

The chemical, a highly alkaline colorless liquid with a strong ammonia odor, was identified as triethylamine using fourier transform infrared and proton nuclear magnetic resonance spectroscopy and gas chromatography (GC) coupled with mass spectrometry.

Karl Fischer titration indicated 221 ppm water. Elemental analyses for carbon, hydrogen, and nitrogen were in agreement with the theoretical values for triethylamine. GC with flame ionization detection (FID) indicated one major peak and no impurities with areas greater than 0.1% relative to the total peak area. The overall purity of lot CE/04/01 was determined to be greater than 99%.

An additional analysis was performed to determine if triethylamine oxide (TEAO), a degradation product that can be found in the test chemical from reaction with oxygen, was present. The presence of TEAO was determined by controlled thermal degradation of TEAO to diethylamine^40^ with subsequent analysis using GC coupled with mass spectrometry. Results indicated that, if present, the concentration of TEAO was less than 0.1%.

To ensure stability, the test chemical was stored at controlled room temperature in the original shipping containers (55-gallon metal drums). Periodic reanalyses of the bulk chemical were performed during the 2-week and 3-month studies using GC/FID, and no degradation of the bulk chemical was detected.

## Vapor Generation and Exposure System

Triethylamine was pumped through a preheater (2-week studies) into a heated glass column filled with glass beads to increase the surface area for evaporation. Heated nitrogen entering the column from below vaporized the chemical as it was conveyed out of the generator and into a short vapor distribution manifold. Concentration in the manifold was determined by the chemical pump and nitrogen flow rates. The pressure in the distribution manifold was kept fixed to ensure consistent flow through the manifold and into the chambers as the flow of vapor to each chamber was adjusted. Precision metering valves controlled flow to each chamber. Three-way exposure valves, mounted downstream from all metering valves directed all chemical to exhaust until the generation system was stable and exposures were ready to proceed. When the exposure started, the three-way valve was rotated to allow the flow of triethylamine vapor through the Teflon® delivery line into the chamber inlet duct where it was further mixed and diluted with conditioned chamber air to achieve the desired exposure concentration.

The study laboratory designed the inhalation exposure chamber (Harford Systems Division of Lab Products, Inc., Aberdeen, MD) so that uniform vapor concentrations could be maintained throughout the chamber with the catch pans in place. The total active mixing volume of each chamber was 1.7 m^3^. A condensation particle counter was used with and without animals in the exposure chambers to ensure that triethylamine vapor, and not aerosol, was produced. No particle counts above the minimum resolvable level (approximately 200 particles/cm^3^) were detected.

## Vapor Concentration Monitoring

Summaries of the chamber vapor concentrations are given in Table F-2 and Table F-3. Concentrations in the exposure chambers were monitored by an on-line gas chromatograph. Samples were drawn from each exposure chamber approximately every 20 minutes during each 6-hour exposure using a stream-select valve. This valve directed a continuous stream of sampled atmosphere to a sampling valve with a sample loop. Both valves were mounted in a dedicated oven. A vacuum regulator maintained a constant pressure in the sample loop to compensate for variations in sample line pressure. An in-line flow meter between the vacuum regulator and gas chromatograph allowed digital measurement of sample flow.

The on-line gas chromatograph was checked throughout the day for instrument drift against an on-line standard of triethylamine vapor supplied by a standard generator. The on-line gas chromatograph was calibrated by a comparison of chamber concentration data to data from grab samples that were collected with acrylic ester sampling tubes and extracted with methylene chloride containing cyclopentylamine as an internal standard and analyzed by an off-line gas chromatograph. Known values of chamber atmosphere were sampled at a constant flow rate ensured by a calibrated critical orifice. The off-line gas chromatograph was calibrated with gravimetrically prepared standards of triethylamine and the internal standard (triethylamine) in methylene chloride.

## Chamber Atmosphere Characterization

Buildup and decay rates for chamber vapor concentrations were determined with and without animals present in the chambers. At a chamber airflow rate of 15 air changes per hour, the theoretical value for the time to achieve 90% of the target concentration after the beginning of vapor generation (T_90_) and the time for the chamber concentration to decay to 10% of the target concentration after vapor generation was terminated (T_10_) was approximately 9.4 minutes. A T_90_ value of 12 minutes was selected for all studies.

The uniformity of vapor concentration in the inhalation exposure chambers without animals present was evaluated before the 3-month studies began; in addition, concentration uniformity with animals in the chambers was measured once during the 2-week and 3-month studies. The vapor concentration was measured using the on-line gas chromatograph with the stream-selection valve fixed in one position to allow continuous monitoring from a single input line. Chamber concentration uniformity was maintained throughout the studies.

The persistence of triethylamine in the chambers after vapor delivery ended was determined by monitoring the vapor concentration in the 1,000 ppm chambers with animals present in the 2-week studies and in the 200 ppm chambers with and without animals present in the 3-month studies. In the 2-week studies, the concentration decreased to 1% of the target concentration within 21 minutes. In the 3-month studies, the concentration decreased to 1% of the target concentration within 56 minutes with animals present and within 22 minutes without animals present.

Test article stability in the distribution lines and low and high exposure concentration chambers was characterized during the 2-week and 3-month studies; characterization of the chamber test atmosphere during the first and last 2 hours of one generation day was conducted with animals present in the exposure chambers. Similar stability studies were conducted prior to the start of the 3-month studies; in these studies, exposure chamber measurements were taken from unoccupied chambers. Additional samples were collected from the generator reservoir during the 2-week studies and prior to the 3-month studies. Samples of the bulk chemical taken from the generator reservoir were diluted with methylene chloride containing diethylamine as an internal standard and analyzed by GC. Samples of the test atmosphere from the distribution lines and exposure chambers were collected with sorbent tubes, extracted with methylene chloride, and analyzed using GC. To assess whether impurities or degradation products co-eluted with the test chemical or the solvent, a second analysis of the test atmosphere samples was performed with GC using a polar column that permitted resolution of compounds with similar boiling points but small differences in polarity. Some of the samples of the test atmosphere from the distribution lines and exposure chambers in these studies contained one impurity with an area greater than 0.1% of the total peak area; the identity of this impurity was confirmed as diethylamine using GC with mass spectrometric detection. The highest concentrations of diethylamine noted in the test atmosphere samples during the 2-week studies and prior to and during the 3-month studies were 0.16%, 0.24%, and 0.34% of the total peak areas, respectively; the presence of this impurity was attributed to artifacts of sample collection or formation in the injector port. Diethylamine was shown to be present at less than 0.1% in all samples from the generator reservoir. No evidence of degradation of the test chemical was detected, and no other impurities were detected in any of the reservoir, distribution line, or exposure chamber samples.

## Animal Welfare

Animal care and use are in accordance with the Public Health Service policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by the Association of Laboratory Animal Care International. Studies were approved by the Battelle Toxicology Northwest Animal Care and Use Committee and conducted in accordance with all relevant NIH and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Two-week Studies

Male and female F344/N rats and B6C3F1/N mice were obtained from Taconic Farms, Inc. (Germantown, NY). On receipt, the rats and mice were 4 weeks old. Animals were quarantined for 13 days and were 6 weeks old on the first day of the studies. Groups of five male and five female rats and mice were exposed to triethylamine via whole body inhalation at concentrations of 0, 100, 200, 400, 800, or 1,000 ppm. These exposure concentrations were based upon results reported for diethylamine inhalation studies conducted in mice^41^ and rats.^42^ Animals were exposed for 6 hours plus T_90_ (12 minutes) per day, 5 days per week for 16 (rats) or 17 (mice) days. Rats were exposed for a total of 12 days and mice for 13 days. Feed was available ad libitum except during exposure periods; water was available ad libitum. Rats and mice were housed individually. Clinical findings were recorded twice daily for rats and mice. The animals were weighed initially, on days 6 and 13, and at the end of the studies. Before the studies began, five male and five female rats and mice were randomly selected for parasite evaluation and gross observation for evidence of disease. At the end of the studies, serologic analyses were performed on five male and five female chamber control rats and mice using the protocols of the NTP Sentinel Animal Program; all results were negative (Appendix H). Details of the study design and animal maintenance are summarized in Table 1.

Table 1 Experimental Design and Materials and Methods in the Inhalation Studies of Triethylamine

Two-week Studies | Three-month Studies
Study Laboratory
Battelle Toxicology Northwest (Richland, WA) | Battelle Toxicology Northwest (Richland, WA)
Strain and Species
F344/N rats | F344/N rats
B6C3F1/N mice | B6C3F1/N mice
Animal Source
Taconic Farms, Inc. (Germantown, NY) | Taconic Farms, Inc. (Germantown, NY)
Time Held Before Studies
13 days | Rats: 12 days (males) or 13 days (females)
| Mice: 12 days
Average Age When Studies Began
6 weeks | 5 to 6 weeks
Date of First Exposure
September 23, 2002 | Rats: January 20 (males) or 21 (females), 2003
| Mice: January 20, 2003
Duration of Exposure
6 hours plus T_90_ (12 minutes) per day, 5 days per week, for 16 (rats) or 17 (mice) days | 6 hours plus T_90_ (12 minutes) per day, 5 days per week, for 14 weeks
Date of Last Exposure
Rats: October 8, 2002 | Rats: April 21 (males) or 22 (females), 2003
Mice: October 9, 2002 | Mice: April 23 (males) or 24 (females), 2003
Necropsy Dates
Rats: October 9, 2002 | Rats: April 22 (males) or 23 (females), 2003
Mice: October 10, 2002 | Mice: April 24 (males) or 25 (females), 2003
Average Age at Necropsy
8 weeks | 18 to 19 weeks
Size of Study Groups
5 males and 5 females | 10 males and 10 females
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights. | Same as 2-week studies
Animals per Cage
1 | 1
Method of Animal Identification
Tail tattoo | Same as 2-week studies
Diet
NTP-2000 irradiated wafers (Zeigler Brothers, Inc., Gardners, PA), available ad libitum (except during exposure periods); changed weekly | Same as 2-week studies
Water
Tap water (Richland, WA, municipal supply) via automatic watering system (Edstrom Industries, Waterford, WI); available ad libitum | Same as 2-week studies
Cages
Stainless steel, wire bottom (Lab Products, Inc., Seaford, DE); changed weekly | Same as 2-week studies; rotated weekly
Cageboard
Untreated paper cage pan liner (Sheperd Specialty Papers, Kalamazoo, MI), changed daily | Same as 2-week studies
Chamber Air Supply Filters
Single HEPA, changed annually; charcoal (RSE, Inc., New Baltimore, MI), new at study start; Purafil (Environmental Systems, Lynnwood, WA), new at study start | Same as 2-week studies
Chambers
Stainless steel, excreta pan at each of six levels (Lab Products, Inc., Seaford, DE); chambers changed weekly; excreta pans changed daily | Same as 2-week studies
Chamber Environment
Temperature: 72° ± 3°F | Same as 2-week studies
Relative humidity: 50% ± 15%
Room fluorescent light: 12 hours/day
Chamber air changes: 15 ± 2/hour
Exposure Concentrations
0, 100, 200, 400, 800, and 1,000 ppm | 0, 12.5, 25, 50, 100, and 200 ppm
Type and Frequency of Observation
Observed twice daily; animals were weighed initially, on days 6 and 13, and at the end of the studies; clinical findings were recorded twice daily on exposure days. | Observed twice daily; core study animals were weighed initially, on day 10 (female rats), day 11 (male rats and male and female mice), weekly thereafter, and at the end of the studies; clinical findings were recorded twice daily.
Method of Kill
Carbon dioxide asphyxiation | Same as 2-week studies
Necropsy
Necropsies were performed on all animals. Organs weighed were heart, right kidney, liver, lung, right testis, and thymus. | Necropsies were performed on all animals. Organs weighed were heart, right kidney, liver, lung, right testis, and thymus.
Clinical Pathology
None | Blood was collected from the retroorbital sinus of clinical pathology rats on days 3 and 23 and from core study animals at the end of the studies for hematology and clinical chemistry (rats only). Hematology: hematocrit; packed cell volume; hemoglobin; erythrocyte, reticulocyte, and platelet counts; Howell-Jolly bodies (mice); mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; and leukocyte counts and differentials. Clinical chemistry: urea nitrogen, creatinine, total protein, albumin, globulin, alanine aminotransferase, alkaline phosphatase, creatine kinase, sorbitol dehydrogenase, and bile salts
Histopathology
Histopathology was performed on 0, 800, and 1,000 ppm rats and mice. In addition to gross lesions and tissue masses, the following tissues were examined: eye, lung, and nose. In mice, these tissues were examined to a no-effect level in the remaining exposure groups. | Complete histopathology was performed on 0 and 200 ppm core study rats and mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, eyes, gallbladder (mice), Harderian gland, heart and aorta, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, larynx, liver, lung (with bronchus), lymph nodes (mandibular, mesenteric, bronchial, mediastinal), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle, skin, spleen, stomach (forestomach and glandular), testis (with epididymis), thymus, thyroid gland, trachea, urinary bladder, and uterus. In addition, the eyes, larynx, lung, nose, and trachea in the remaining groups of rats and mice, and the large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, liver, and stomach (forestomach and glandular) in the remaining groups of rats were examined.
Sperm Motility and Vaginal Cytology
None | At the end of the studies, sperm samples were collected from male animals in the 0, 50, 100, and 200 ppm groups for sperm motility evaluations. The following parameters were evaluated: spermatid heads per testis and per gram testis, spermatid counts, and epididymal spermatozoa motility and concentration. The left cauda, left epididymis, and left testis were weighed. Vaginal samples were collected for up to 12 consecutive days prior to the end of the studies from females exposed to 0, 50, 100, or 200 ppm for vaginal cytology evaluations. The percentage of time spent in the various estrous cycle stages and estrous cycle length were evaluated.

Necropsies were performed on all rats and mice on the day following the last exposure. The heart, right kidney, liver, lung, right testis, and thymus were weighed. Histopathologic examinations were performed on all chamber control and 800 and 1,000 ppm rats and mice, and tissues were examined to a no-effect level in the remaining exposure groups. Table 1 lists the tissues and organs examined.

## Three-month Studies

Male and female F344/N rats and B6C3F1/N mice were obtained from Taconic Farms, Inc. (Germantown, NY). On receipt, the rats and mice were 3 to 4 weeks old. Animals were quarantined for 12 (male rats and male and female mice) or 13 days (female rats) and were 5 to 6 weeks old on the first day of the studies. Before the studies began, five male and five female rats and mice were randomly selected for parasite evaluation and gross observation for evidence of disease. Serologic analyses were performed on five male and five female sentinel rats and mice at 2 weeks and on five male and five female chamber control rats and mice at the end of the studies using the protocols of the NTP Sentinel Animal Program; all results were negative (Appendix H).

Groups of 10 male and 10 female rats and mice were exposed to triethylamine via whole body inhalation at concentrations of 0, 12.5, 25, 50, 100, or 200 ppm, 6 hours plus T_90_ (12 minutes) per day, 5 days per week for 14 weeks. Groups of 10 male and 10 female clinical pathology rats were exposed to the same concentrations for 23 days. Feed was available ad libitum except during exposure periods; water was available ad libitum. Rats and mice were housed individually. Clinical findings were recorded twice daily for core study rats and mice. Core study animals were weighed initially, on day 10 (female rats), day 11 (male rats and male and female mice), weekly thereafter, and at the end of the studies. Details of the study design and animal maintenance are summarized in Table 1.

Animals were anesthetized with carbon dioxide, and blood was collected from the retroorbital sinus of clinical pathology rats on days 3 and 23 and from core study rats and mice at the end of the studies for hematology and clinical chemistry (rats only) analyses. Blood samples for hematology analyses were placed in tubes containing potassium EDTA. Packed cell volume; hemoglobin concentration; erythrocyte, platelet, and leukocyte counts; mean cell volume; mean cell hemoglobin; and mean cell hemoglobin concentration were determined using an Abbott Cell-Dyn 3700 Analyzer (Abbott Diagnostics Systems, Abbott Park, IL). Manual hematocrit values were determined using a microcentrifuge (Heraeus Haemofuge; Hanau, Germany) and a Damon/IEC capillary reader (International Equipment Co., Needham Heights, MA) for comparison to Cell-Dyn values for packed cell volume. Blood smears were stained with Romanowsky-type aqueous stain in a Wescor 1700 aerospray slide stainer (Wescor, Inc., Logan, UT). Leukocyte differential counts were based on classifying a minimum of 100 white cells. Reticulocytes were stained with new methylene blue and enumerated as a reticulocyte:erythrocyte ratio using the Miller disc method.^43^ Blood samples for clinical chemistry analyses were placed in tubes without anticoagulant and containing a separator gel, allowed to clot, and centrifuged. Parameters were determined using a Roche Hitachi 912 System (Roche Diagnostic Corporation, Indianapolis, IN). Table 1 lists the parameters measured.

At the end of the 3-month studies, samples were collected for sperm motility and vaginal cytology evaluations on rats and mice exposed to 0, 50, 100, and 200 ppm. The parameters evaluated are listed in Table 1. For 12 consecutive days prior to scheduled terminal kill, the vaginal vaults of the females were moistened with saline, if necessary, and samples of vaginal fluid and cells were stained. Relative numbers of leukocytes, nucleated epithelial cells, and large squamous epithelial cells were determined and used to ascertain estrous cycle stage (i.e., diestrus, proestrus, estrus, and metestrus). Male animals were evaluated for sperm count and motility. The left testis and left epididymis were isolated and weighed. The tail of the epididymis (cauda epididymis) was then removed from the epididymal body (corpus epididymis) and weighed. Test yolk (rats) or modified Tyrode’s buffer (mice) was applied to slides and a small incision was made at the distal border of the cauda epididymis. The sperm effluxing from the incision were dispersed in the buffer on the slides, and the numbers of motile and nonmotile spermatozoa were counted for five fields per slide by two observers. Following completion of sperm motility estimates, each left cauda epididymis was placed in buffered saline solution. Caudae were finely minced, and the tissue was incubated in the saline solution and then heat fixed at 65°C. Sperm density was then determined microscopically with the aid of a hemacytometer. To quantify spermatogenesis, the testicular spermatid head count was determined by removing the tunica albuginea and homogenizing the left testis in phosphate-buffered saline containing 10% dimethyl sulfoxide. Homogenization-resistant spermatid nuclei were counted with a hemacytometer.

Necropsies were performed on all animals. The heart, right kidney, liver, lung, right testis, and thymus were weighed. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin, processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin. Complete histopathologic examinations were performed by the study laboratory pathologist on all chamber control and 200 ppm animals. In addition, the eyes, larynx, lung, nose, and trachea in the remaining groups of rats and mice, and the large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, liver, and stomach (forestomach and glandular) in the remaining groups of rats were examined. Table 1 lists the tissues and organs routinely examined.

After a review of the laboratory reports and selected histopathology slides by a quality assessment (QA) pathologist, the findings and reviewed slides were submitted to a NTP Pathology Peer Review (PPR) coordinator for a second independent review. Any inconsistencies in the diagnoses made by the study laboratory and QA pathologists were resolved by the NTP PPR process. Final diagnoses for reviewed lesions represent a consensus of the PPR or a consensus between the study laboratory pathologist, NTP pathologist, QA pathologist(s), and the PPR coordinator. Details of these review procedures have been described, in part, by Maronpot and Boorman^44^ and Boorman et al.^45^ Because of the demise of the original NTP pathologist prior to completion of the Toxicity Study Report and the development of the Nonneoplastic Lesion Atlas (NNLA), a second NTP pathologist was assigned to this study to equate the terminology used in the current Toxicity Study Report to that recommended in the NNLA. As a result, three additional PPRs were performed to assess the nasoturbinates of the 3-month mice, the eyes of the 2-week rats and mice, and the eyes of 3-month rats. The recommendations of those PPRs were then incorporated into the final diagnoses used in this Toxicity Study Report.

## Statistical Methods

### Calculation and Analysis of Lesion Incidences

The incidences of lesions are presented in Appendix A as the numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. The Fisher exact test,^46^ a procedure based on the overall proportion of affected animals, was used to determine significance.

### Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between exposed and control groups in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^47^ and Williams.^48,49^ Hematology, clinical chemistry, spermatid, and epididymal spermatozoal data, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley^50^ (as modified by Williams^51^) and Dunn.^52^ Jonckheere’s test^53^ was used to assess the significance of the dose-related trends and to determine whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic dose-related trend (Dunnett’s or Dunn’s test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey^54^ were examined by NTP personnel, and implausible values were eliminated from the analysis. Proportions of regular cycling females in each exposed group were compared to the control group using the Dunn’s test.^52^ Tests for extended periods of estrus, diestrus, metestrus, and proestrus, as well as skipped estrus and skipped diestrus were constructed based on a Markov chain model proposed by Girard and Sager.^55^ For each exposure group, a transition probability matrix was estimated for transitions among the proestrus, estrus, metestrus, and diestrus stages, with provision for extended stays within each stage as well as for skipping estrus or diestrus within a cycle. Equality of transition matrices among exposure groups and between the control group and each exposed group was tested using chi-square statistics.

## Quality Assurance Methods

The 2-week and 3-month studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations.^56^

## Genetic Toxicology

### Bacterial Mutagenicity Test Protocol

Testing was performed as reported by Zeiger et al.^39^ Triethylamine was sent to the laboratory as a coded aliquot from Radian Corporation (Austin, TX). It was incubated with the Salmonella typhimurium tester strains TA98, TA100, TA1535, and TA1537 either in buffer or S9 mix (metabolic activation enzymes and cofactors from Aroclor 1254-induced male Sprague-Dawley rat or Syrian hamster liver) for 20 minutes at 37°C. Top agar supplemented with L-histidine and d-biotin was added, and the contents of the tubes were mixed and poured onto the surfaces of minimal glucose agar plates. Histidine-independent mutant colonies arising on these plates were counted following incubation for 2 days at 37°C.

Each trial consisted of triplicate plates of concurrent positive and negative controls and five doses of triethylamine. The high dose was 10,000 µg/plate, which induced toxicity in some trials. All trials were repeated.

In this assay, a positive response is defined as a reproducible, dose-related increase in histidine-independent (revertant) colonies in any one strain/activation combination. An equivocal response is defined as an increase in revertants that is not dose related, is not reproducible, or is not of sufficient magnitude to support a determination of mutagenicity. A negative response is obtained when no increase in revertant colonies is observed following chemical treatment. There is no minimum percentage or fold increase required for a chemical to be judged positive or weakly positive, although positive calls are typically reserved for increases in mutant colonies that are at least twofold over background.

### Mouse Peripheral Blood Micronucleus Test Protocol

A detailed discussion of this assay is presented by MacGregor et al.^57^ At the end of the 3-month toxicity study, peripheral blood samples were obtained from male and female mice. Smears were immediately prepared and fixed in absolute methanol. The methanol-fixed slides were stained with acridine orange and coded. Slides were scanned to determine the frequency of micronuclei in 1,000 normochromatic erythrocytes (NCEs) in each of 10 animals per exposure group. In addition, the percentage of polychromatic erythrocytes (PCEs) among a population of 1,000 erythrocytes was scored for each exposure group as a measure of bone marrow toxicity.

The results were tabulated as the mean of the pooled results from all animals within a treatment group plus or minus the standard error of the mean. The frequency of micronucleated cells among NCEs was analyzed by a statistical software package that tested for increasing trend over exposure groups with a one-tail Cochran-Armitage trend test, followed by pairwise comparisons between each exposed group and the control group. In the presence of excess binomial variation, as detected by a binomial dispersion test, the binomial variance of the Cochran-Armitage test was adjusted upward in proportion to the excess variation. In the micronucleus test, an individual trial is considered positive if the trend test P value is less than or equal to 0.025 or if the P value for any single exposed group is less than or equal to 0.025 divided by the number of exposed groups. A final call of positive for micronucleus induction is preferably based on reproducibly positive trials (as noted above). Ultimately, the final call is determined by the scientific staff after considering the results of statistical analyses, the reproducibility of any effects observed, and the magnitudes of those effects.

### Evaluation Protocol

These are the basic guidelines for arriving at an overall assay result for assays performed by the National Toxicology Program. Statistical as well as biological factors are considered. For an individual assay, the statistical procedures for data analysis have been described in the preceding protocols. There have been instances, however, in which multiple samples of a chemical were tested in the same assay, and different results were obtained among these samples and/or among laboratories. Results from more than one aliquot or from more than one laboratory are not simply combined into an overall result. Rather, all the data are critically evaluated, particularly with regard to pertinent protocol variations, in determining the weight of evidence for an overall conclusion of chemical activity in an assay. In addition to multiple aliquots, the in vitro assays have another variable that must be considered in arriving at an overall test result. In vitro assays are conducted with and without exogenous metabolic activation. Results obtained in the absence of activation are not combined with results obtained in the presence of activation; each testing condition is evaluated separately. The results presented in the Abstract of this Toxicity Study Report represent a scientific judgment of the overall evidence for activity of the chemical in an assay.