# Introduction

Figure 1

Triethylamine (CASRN 121-44-8; Chemical Formula: C_6_H_15_N; Molecular Weight: 101.19)

Synonyms: (Diethylamino) ethane; ethanamine, N,N-diethyl- (9CI); N,N-diethylethanamine; triethyl-(diethylamino) ethaneamine.

## Chemical and Physical Properties

Triethylamine is a colorless liquid with a strong ammonia-like odor (odor threshold 0.48 ppm) and is miscible in water, ethanol, and ethyl ether. Triethylamine has a relatively high vapor pressure (54 mm Hg at 20°C),^1^ and the vapor is explosive when exposed to heat or flame. Triethylamine is a dangerous fire hazard when exposed to heat, flame, or oxidizers and when heated to decomposition, it emits toxic nitrogen oxide fumes.^2^

## Production, Use, and Human Exposure

Triethylamine is produced by reacting ammonia with ethanol, N,N-diethylacetamide with lithium aluminum hydride, or ethyl chloride with ammonia under heat and pressure.^3^ Large-scale production of triethylamine is generally by high temperature, high pressure reactions of ammonia and an alcohol over a dehydration catalyst or a dehydrogenation catalyst.^4^ Yields of mixed amines from the reaction of ammonia and alcohol are high (≥ 80%). Pure amines are obtained by continuous extractions and distillations.

Triethylamine is listed as a high production volume chemical, indicating that greater than 1 million pounds were produced in or imported into the United States in 1990 and/or 1994.^5^ Nonconfidential production volume information indicates that production ranged from 10 to 50 million pounds in 1994, 1998, and 2002.^5^

The largest use of triethylamine is as a catalyst to cure the resin systems incorporated into sand cores for foundry molds.^6^ In this procedure, triethylamine is usually stored in a liquid form at room temperature and during its use, it is vaporized and introduced into the system as a gas.^7,8^ Workers must wear appropriate eye and respiratory protection,^9^ and proper ventilation of the work area is necessary.^10^

Annually in the United States, approximately 5 million pounds of triethylamine are used as a curing catalyst in phenol-formaldehyde particle board adhesives, 2 to 3 million pounds of triethylamine are used for the precipitation and purification of penicillin and cephalosporin antibiotics, and 1 to 2 million pounds of triethylamine are used in the interfacial polymerization process for the production of polycarbonate resins. Triethylamine is also used as an ingredient in sealing paint (0.5% w/w)^11^; in the manufacture of some paper and board adhesives; as a stabilizer for the chlorinated solvents perchlorethylene and trichloroethylene^6^; as an antilivering agent for urea- and melamine-based enamels; in the recovery of gelled paint vehicles; as an accelerator activator for rubber; as a corrosion inhibitor; as a propellant; as a wetting, penetrating, and waterproofing agent of quaternary ammonia compounds; as an emulsifying agent for dyes; for the production of textile treatment agents; as an ingredient of photographic development accelerator; for drying printing inks; in carpet cleaners; in the production of herbicides and pesticides and in the preparation of emulsifiers for pesticides; in nonnutritive sweeteners, ketenes, and salts; and for the desalination of water.^12^

The National Institute for Occupational Safety and Health (NIOSH)^13^ estimated that 68,091 workers were potentially exposed to triethylamine in the workplace annually. Occupational exposure to triethylamine can occur through inhalation and dermal contact in industries where this chemical is used or produced. Because triethylamine is vaporized when used in mold production in iron foundries, inhalation of the vapors is a major route of occupational exposure. The general population may be exposed to triethylamine by inhalation of ambient air, ingestion of food, and dermal contact with this chemical or products containing triethylamine.

## Regulatory Status

The Occupational Safety and Health Administration airborne permissible exposure limit for triethylamine is 25 ppm (100 mg/m^3^) averaged over an 8-hour workshift.^14^ The American Conference of Governmental Industrial Hygienists^15^ recommended airborne exposure limit is 1 ppm triethylamine averaged over an 8-hour workshift and 3 ppm as a 15-minute short-term exposure limit (STEL). NIOSH^16^ recommended an exposure limit of 10 ppm (time-weighted average; TWA), a STEL of 15 ppm, and an immediately dangerous to life value of 200 ppm. These exposure limits were based on the adverse effects of triethylamine on the eyes and skin.

## Absorption, Distribution, Metabolism, Excretion, and Toxicokinetics

No information was found on the absorption, distribution, metabolism, or excretion of triethylamine in rodents.

Åkesson et al.^17,18^ investigated the absorption, distribution, metabolism, excretion, and toxicokinetics of triethylamine in five healthy men. The subjects were exposed to triethylamine concentrations of 10, 25, 35, or 50 mg/m^3^ (2.4, 6.0, 8.4, or 12.0 ppm) for 4 or 8 hours. The concentrations of triethylamine in exhaled air were about 20% of those in inhaled air indicating significant absorption. Analysis of urine showed that most of the triethylamine was excreted unchanged. An average of 24% of the triethylamine was oxidatively metabolized into triethylamine-N-oxide, but with a wide interindividual variation of 15% to 36%. A similar observation was reported following exposure of 20 workers employed at a polyurethane foam manufacturing plant to approximately 500 µmol (calculated as TWA × pulmonary ventilation) triethylamine per day.^19^ Less than 0.3% of the inhaled triethylamine was excreted as diethylamine. Exogenous aliphatic amines are generally metabolized by monoamine oxidase and diamine oxidase. Monoamine oxidase catalyses the deamination of primary, secondary, and tertiary amines to form ammonia, which is ultimately converted to urea.^20^ The plasma and urinary concentrations of triethylamine and triethylamine-N-oxide decreased rapidly after the end of the exposure. The mean urinary excretion half-life for triethylamine and the oxide were approximately 3 and 4 hours, respectively.

Åkesson et al.^18^ also investigated the disposition of triethylamine in four healthy men after a single oral dose of 25 mg or an intravenous dose of 15 mg. Triethylamine was efficiently absorbed from the gastrointestinal tract after oral administration. Total doses recovered in urine as triethylamine and triethylamine-N-oxide after oral and intravenous administration were 90% and 97%, respectively. Triethylamine was excreted into the gastric juice where levels were approximately 30 times the levels in plasma. Excretion of triethylamine by exhalation was minimal. The average plasma and urine half-lives following oral administration were 2.9 and 2.8 hours, respectively.

## Toxicity

### Experimental Animals

In early studies of triethylamine toxicity, Carpenter et al.^21^ reported that acute inhalation exposure of guinea pigs to 2,000 ppm for 2 hours resulted in the death of four of six animals. Exposure to 1,000 ppm for 4 hours resulted in the death of two of six animals and no deaths were observed after 4 hours of exposures to 250 or 500 ppm triethylamine. In other acute studies, Brieger and Hodes^22^ exposed rabbits (strain not reported) to 50 or 100 ppm (210 or 414 mg/m^3^) triethylamine vapor 7 hours/day, 5 days per week for 6 weeks. Exposure to 100 ppm resulted in pulmonary edema, hemorrhage, moderate peribronchitis, and vascular thickening. Extrapulmonary effects were noted in the kidney and liver and were characterized as parenchymal degeneration with cell necrosis. Similar but less severe lesions were observed in the lung, kidney, and liver of animals exposed to 50 ppm. Severe ocular irritation was observed in rabbits exposed to 50 or 100 ppm triethylamine for 30 days. A researcher accidentally exposed to 50 ppm triethylamine (duration unknown) during this animal study experienced severe corneal erosion and edema.

In a subchronic inhalation study, albino rats exposed to 3.14 ppm (13.01 mg/m^3^) triethylamine for 3 months exhibited changes in the lungs, brain, and liver.^23^ In the lungs, there was infiltration of the perivascular connective tissue by white blood cells, thickening of the interalveolar walls and shedding of the alveolar epithelium. In the brain, there was swelling, disruption of nuclei, necrosis, disappearance of neurons, reduced cytochrome C oxidase activity, accumulation of lipids in the cerebral cortex, and reduced staining intensity of sulfhydryl groups. In the liver, there was a reduction in glycogen content. These effects were not observed after exposure to 0.04 or 0.4 ppm (0.16 or 1.71 mg/m^3^) triethylamine.

Rats exposed to concentrations of 7.2 to 19 ppm (30 to 80 mg/m^3^) triethylamine, 3 hours/day for 6 months exhibited decreased body weights, changes in nervous system function (details not provided), hypohemoglobinemia, increased blood reticulocytes, and chronic inflammation of the lungs.^3^

Lynch et al.^24^ exposed male and female F344 rats to 0, 25, or 247 ppm triethylamine vapors, 6 hours/day, 5 days a week for up to 28 weeks. No significant treatment-related effects were observed on body weights, hematology, clinical chemistry, or electrocardiographic indices after exposure to either concentration. No histopathologic lesions were detected in any of the organs examined, including the nasal passages.

Dermal exposure to triethylamine has been demonstrated to cause severe skin damage in several species of laboratory animals. Skin injury is attributed to the potent alkalinity of triethylamine. A 70% solution of triethylamine placed on the skin of guinea pigs for 2 hours caused severe skin injury.^25^ Severe skin damage was also observed in New Zealand white rabbits that had 0.5 mL triethylamine applied to intact or abraded occluded skin for 3 minutes^26,27^ or 24 hours.^28^ Dermal application of 2,000 or 5,000 mg/kg triethylamine to rabbits (strain not provided) resulted in 75% and 100% mortality, respectively.^29^ Severe toxicity leading to death was observed in New Zealand white rabbits that had 1 or 2 mL/kg triethylamine applied to the skin for 24 hours.^30,31^ Necropsies of dead rabbits revealed dark lungs and kidneys, pale spleen, and pale, mottled liver.

### Humans

Occupational exposure to triethylamine is reported to cause irritation of the respiratory tract, the eyes, and mucous membranes; however, published studies evaluating the pulmonary effects of triethylamine on humans could not be found in the literature. Reports on human exposures were primarily concerned with reported eye irritation and vision symptoms of blurriness, halo vision and glaucopsia (blue, hazy vision).^32,33,22,34^ These symptoms are typically short-lived, lasting about an hour after the end of exposure and are attributed to light scattering associated with corneal irritation and edema.^35^ Corneal irritation and edema result from direct action of triethylamine on the corneal epithelium.

Åkesson et al.^33^ exposed human volunteers to 2.5 to 12 ppm (10 to 48 mg/m^3^) triethylamine for 4 to 8 hours. Severe visual disturbances were reported in two volunteers exposed to 12 ppm triethylamine vapor for 4 hours. Symptoms included hazing of visual fields, bluish halos around lights, and slight ocular irritation. Ocular examination revealed a slight decrease in visual acuity and pronounced corneal edema. Symptoms disappeared after 4 to 4.5 hours. Similar but less severe effects occurred after 2 hours of exposure to 8.5 ppm (34 mg/m^3^); slight visual disturbance was reported after 4 to 6 hours of exposure to 4.5 ppm (18 mg/m^3^), and no adverse effects were noted after exposure to 2.5 ppm (10 mg/m^3^) triethylamine for 8 hours. In a subsequent study, Åkesson et al.^32^ reported that five of 19 workers exposed to triethylamine at a polyurethane foam production plant reported visual disturbances described as foggy vision, blue haze, and sometimes halo phenomena. At the sites within the plant where workers reported symptoms, the triethylamine concentrations ranged from 1 to 6 ppm (4 to 24 mg/m^3^). No effects were observed when the triethylamine concentrations were decreased to 1.5 ppm (6 mg/m^3^). Visual disturbances in workers have been correlated with occupational exposures to triethylamine vapor in other studies.^36,35,8^

## Carcinogenicity

Information on the carcinogenicity of triethylamine in humans or animals is sparse. In a Danish foundry, molders exposed to a variety of chemicals, including triethylamine, had a significantly increased mortality due to bladder cancer when compared to other skilled workers.^37^ Workers were followed for up to 10 years. Coadministration of 0.5% (5,000 mg/kg feed) triethylamine hydrochloride (37 mMol/kg feed) and 0.5% nitrite in feed to SIV50 rats for 1 year did not result in detectable tumors.^38^ Triethylamine was not administered as a single compound to rats in this study.

## Genetic Toxicity

Triethylamine was not mutagenic in Salmonella typhimurium strains TA98, TA100, TA1535, or TA1537, when tested up to a maximum of 10,000 µg/plate with or without induced rat or hamster liver S9 activation enzymes (Zeiger et al.^39^; Appendix B).

## Study Rationale

Triethylamine was nominated by the International Union, United Automobile, Aerospace and Agricultural Implement Workers of America based on its widespread use and resulting occupational exposures, concern regarding respiratory and ocular effects, and the lack of chronic toxicity and carcinogenicity data. Chronic studies of triethylamine were not conducted because its subchronic toxicity was similar to that of diethylamine, and there was greater interest in a chronic study of diethylamine because of its potential to form nitrosamines.