# Appendix H Sentinel Animal Program Sentinel Animal Program

## H.1 Methods

Rodents used in the Carcinogenesis Program of the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that may affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicologic evaluation of chemical compounds. Under this program, the disease state of the rodents is monitored via serology on sera from extra (sentinel) animals in the study rooms. These animals and the study animals are subject to identical environmental conditions. The sentinel animals come from the same production source and weanling groups as the animals used for the studies of chemical compounds.

Serum samples were collected from five male and five female chamber control rats and mice at the end of the 2-week studies. In the 3-month studies, serum samples were collected from five male and five female sentinel rats and mice at 2 weeks and from five male and five female chamber control rats and mice at study termination. Blood from each animal was collected and allowed to clot, and the serum was separated. Samples were processed appropriately, and antibody titers were determined by BioReliance Corporation (Rockville, MD). The laboratory methods and agents for which testing was performed are tabulated below; the times at which samples were collected during the studies are also listed.

Table H-1 Laboratory Methods and Agents Tested for in the Sentinel Animal Program

Method and Test | Time of Collection
Rats
2-week study
ELISA
H-1 (Toolan’s H-1 virus) | Study termination
KRV (Kilham rat virus) | Study termination
Mycoplasma pulmonis | Study termination
PVM (pneumonia virus of mice) | Study termination
RCV/SDA (rat coronavirus/sialodacryoadenitis virus) | Study termination
Sendai | Study termination
3-month study
ELISA
H-1 | 2 weeks
KRV | 2 weeks
Mycoplasma arthritidis | Study termination
M. pulmonis | 2 weeks, study termination
PVM | 2 weeks, study termination
RCV/SDA | 2 weeks, study termination
Sendai | 2 weeks, study termination
Immunofluorescence Assay
Parvovirus | Study termination
Mice
2-week study
ELISA
MHV (mouse hepatitis virus) | Study termination
MVM (minute virus of mice) | Study termination
M. pulmonis | Study termination
PVM | Study termination
Sendai | Study termination
TMEV (Theiler’s mouse encephalomyelitis virus) | Study termination
3-month study
ELISA
Ectromelia virus | Study termination
EDIM (epizootic diarrhea of infant mice) | Study termination
LCM (lymphocytic choriomeningitis virus) | Study termination
Mouse adenoma virus | Study termination
MCMV (mouse cytomegalovirus) | Study termination
MHV | 2 weeks, study termination
MVM | 2 weeks
M. arthritidis | Study termination
M. pulmonis | 2 weeks, study termination
PVM | 2 weeks, study termination
Reovirus | Study termination
Sendai | 2 weeks, study termination
TMEV | 2 weeks, study termination
Immunofluorescence Assay
Parvovirus | Study termination

## H.2 Results

All test results were negative.