# Appendix F Chemical Characterization and Generation of Chamber Concentrations

## F.1 Procurement and Characterization of Triethylamine

Triethylamine was obtained from Alkyl Amines Chemicals, Limited (Maharashtra, India) in one lot (CE/04/01) that was used in the 2-week and 3-month studies. Identity and purity analyses were conducted by the analytical chemistry laboratories at Chemir/Polytech Laboratories, Inc. (Maryland Heights, MO), Galbraith Laboratories, Inc., (Knoxville, TN), and Research Triangle Institute (RTI) (Research Triangle Park, NC), and by the study laboratory at Battelle Toxicology Northwest (Richland, WA). Reports on analyses performed in support of the triethylamine studies are on file at the National Institute of Environmental Health Sciences.

Lot CE/04/01 of the chemical, a highly alkaline colorless liquid with a strong ammonia odor, was identified as triethylamine by Chemir/Polytech, Inc., and RTI using fourier transform infrared (IR) and proton nuclear magnetic resonance (NMR) spectroscopy. RTI also used gas chromatography (GC) with mass spectrometry (MS) to confirm the identification. All spectra were consistent with the literature spectra^78,79^ and the structure of triethylamine. Representative IR, proton NMR, and mass spectra are presented in Figure F-1, Figure F-2, and Figure F-3, respectively.

Chemir/Polytech Laboratories, Inc. determined the moisture content of lot CE/04/01 using Karl Fischer titration. Galbraith Laboratories, Inc., measured the purity of the bulk chemical by elemental analyses. The purity of lot CE/04/01 was also determined by RTI and the study laboratory using GC with flame ionization detection (FID) by systems A and B, respectively (Table F-1).

For lot CE/04/01, Karl Fischer titration indicated 221 ppm water. Elemental analyses for carbon, hydrogen, and nitrogen were in agreement with the theoretical values for triethylamine. GC/FID by system A indicated one major peak and five minor impurity peaks, each with less than 0.1% of the total peak area. GC/FID by system B indicated one major peak and no impurities with areas greater than 0.1% relative to the total peak area. The overall purity of lot CE/04/01 was determined to be greater than 99%.

An additional analysis was performed by the study laboratory to determine if triethylamine oxide (TEAO), a degradation product that can be found in the test chemical from reaction with oxygen, was present. The presence of TEAO was determined by controlled thermal degradation of TEAO to diethylamine^40^ with subsequent analysis using GC/MS by system C. Results indicated that, if present, the concentration of TEAO was less than 0.1%.

To ensure stability, the test chemical was stored at controlled room temperature in the original shipping containers (55-gallon metal drums). Periodic reanalyses of the bulk chemical were performed by the study laboratory during the 2-week and 3-month studies using GC/FID by system B and no degradation of the test chemical was detected.

## F.2 Vapor Generation and Exposure System

A diagram of the vapor generation and delivery system used in the studies is shown in Figure F-4. A bulk supply of triethylamine was held in an 8-gallon stainless steel chemical reservoir and pumped through a preheater (2-week studies only) into the top of a heated glass column filled with glass beads to increase the surface area for evaporation. Heated nitrogen entering the column from below vaporized the chemical as it was conveyed out of the generator. The vapor leaving the generator entered a short vapor distribution manifold. Concentration in the manifold was determined by the chemical pump and nitrogen flow rates. The pressure in the distribution manifold was kept fixed to ensure consistent flow through the manifold and into the chambers as the flow of vapor to each chamber was adjusted. Precision metering valves controlled flow to each chamber. In addition, three-way exposure valves, mounted downstream from all metering valves directed all chemical to exhaust until the generation system was stable and exposures were ready to proceed. When the exposure started, the three-way valve was rotated to allow the flow of triethylamine vapor through the Teflon^®^ delivery line into the chamber inlet duct where it was further mixed and diluted with conditioned chamber air to achieve the desired exposure concentration.

The study laboratory designed the inhalation exposure chamber (Harford Systems Division of Lab Products, Inc., Aberdeen, MD) so that uniform vapor concentrations could be maintained throughout the chamber with the catch pans in place. The total active mixing volume of each chamber was 1.7 m^3^. A condensation particle counter (Model 3022A, TSI Incorporated, St. Paul, MN) was used with and without animals in the exposure chambers to ensure that triethylamine vapor, and not aerosol, was produced. No particle counts above the minimum resolvable level (approximately 200 particles/cm^3^) were detected.

## F.3 Vapor Concentration Monitoring

Summaries of the chamber vapor concentrations are given in Table F-2 and Table F-3. The triethylamine concentrations in the exposure chambers were monitored by an on-line gas chromatograph using system D (Table F-1). Samples were drawn from each exposure chamber through Teflon^®^ sampling lines approximately every 20 minutes during each 6-hour exposure using a 16-port stream-select valve (VALCO Instruments Company, Houston, TX). This valve directed a continuous stream of sampled atmosphere to a six-port sampling valve (VALCO Instruments Company) with a 1 mL sample loop. Both valves were mounted in a dedicated oven maintained at approximately 150°C. A vacuum regulator maintained a constant pressure in the sample loop to compensate for variations in sample line pressure, and a flow meter in line between the vacuum regulator and gas chromatograph allowed digital measurement of sample flow.

The on-line gas chromatograph was checked throughout the day for instrument drift against an on-line standard of triethylamine vapor supplied by a standard generator (Kin-Tek, Precision Calibration Systems, La Marque, TX). The on-line gas chromatograph was calibrated on December 5, 6, and 9, 2002, by a comparison of chamber concentration data to data from grab samples that were collected with acrylic ester sampling tubes (XAD^®^-7, SKC, Inc., Eighty Four, PA) and extracted with methylene chloride containing cyclopentylamine as an internal standard; the grab samples were analyzed by an off-line gas chromatograph using system E. The volumes of gas were sampled at a constant flow rate ensured by a calibrated critical orifice. The off-line gas chromatograph was calibrated with gravimetrically prepared standards of triethylamine and the internal standard in methylene chloride.

## F.4 Chamber Atmosphere Characterization

Buildup and decay rates for chamber vapor concentrations were determined with and without animals present in the chambers. At a chamber airflow rate of 15 air changes per hour, the theoretical value for the time to achieve 90% of the target concentration after the beginning of vapor generation (T_90_) and the time for the chamber concentration to decay to 10% of the target concentration after vapor generation was terminated (T_10_) was approximately 9.4 minutes. For rats and mice in the 2-week studies, T_90_ values ranged from 9 to 10 minutes with animals present; T_10_ values ranged from 9 to 11 minutes with animals present. For rats and mice in the 3-month studies, T_90_ values ranged from 8 to 11 minutes without animals present and from 11 to 15 minutes with animals present; T_10_ values ranged from 9 to 10 minutes without animals present and from 11 to 18 minutes with animals present. A T_90_ value of 12 minutes was selected for all studies.

The uniformity of triethylamine concentration in the inhalation exposure chambers without animals present was evaluated before the 3-month studies began; concentration uniformity with animals in the chambers was measured once during the 2-week and 3-month studies. The vapor concentration was measured using the on-line gas chromatograph and system D (Table F-1) with the stream-selection valve fixed in one position to allow continuous monitoring from a single input line. During the 2-week studies and prior to the 3-month studies, concentrations were measured at 12 chamber positions, one in front and one in back for each of the six possible animal cage unit positions per chamber. During the 3-month studies, concentrations were measured at the regular monitoring port and from sample ports where animals were present. Chamber concentration uniformity was maintained throughout the studies.

The persistence of triethylamine in the chambers after vapor delivery ended was determined by monitoring the concentration in the 1,000 ppm chambers with animals present in the 2-week studies and in the 200 ppm chambers with and without animals present in the 3-month studies. In the 2-week studies, the concentration decreased to 1% of the target concentration within 21 minutes. In the 3-month studies, the concentration decreased to 1% of the target concentration within 56 minutes with animals present and within 22 minutes without animals present.

Test article stability in the distribution lines and low and high exposure concentration chambers was characterized during the 2-week and 3-month studies; characterization of the chamber test atmosphere during the first and last 2 hours of one generation day was conducted with animals present in the exposure chambers. Similar stability studies were conducted prior to the start of the 3-month studies; in these studies, exposure chamber measurements were taken from unoccupied chambers. Additional samples were collected from the generator reservoir during the 2-week studies and prior to the 3-month studies. Samples of the bulk chemical taken from the generator reservoir were diluted with methylene chloride containing diethylamine as an internal standard and analyzed by GC using system F. Samples of the test atmosphere from the distribution lines and exposure chambers were collected with XAD^®^-7 (SKC, Inc.) and ORBO^TM^-32 (Supelco Inc., Bellefonte, PA) sorbent tubes, extracted with methylene chloride, and analyzed using GC by a system similar to system B. To assess whether impurities or degradation products co-eluted with the test chemical or the solvent, a second analysis of the test atmosphere samples was performed with GC by system G using a polar column that permitted resolution of compounds with similar boiling points but small differences in polarity. Some of the samples of the test atmosphere from the distribution lines and exposure chambers in these studies contained one impurity with an area greater than 0.1% of the total peak area; the identity of this impurity was confirmed as diethylamine using GC/MS by system C. The highest concentrations of diethylamine noted in the test atmosphere samples during the 2-week studies and prior to and during the 3-month studies were 0.16%, 0.24%, and 0.34% of the total peak areas, respectively; the presence of this impurity was attributed to artifacts of sample collection or formation in the injector port. Diethylamine was shown to be present at less than 0.1% in all samples from the generator reservoir. No evidence of degradation of the test chemical was detected, and no other impurities were detected in any of the reservoir, distribution line, or exposure chamber samples. These results indicated that triethylamine was stable in the exposure system.

Table F-1 Gas Chromatography Systems Used in the Inhalation Studies of Triethylamine^a^

Detection System | Column | Carrier Gas | Oven Temperature Program
System A
Flame ionization | SPB-1, 60 m × 0.32 mm, 1.0-µm film (Supelco, Inc., Bellefonte, PA) | Nitrogen at 1 mL/minute | 50°C for 5 minutes, then 10°C/minute to 300°C, held for 10 minutes
System B
Flame ionization | PTA-5, 30 m × 0.53 mm, 3.0-µm film (Supelco, Inc.) | Helium at 3 psi head pressure | 35°C for 3 minutes, then 3°C/minute to 75°C, then 7°C/minute to 260°C, held for 1 minute
System C
Mass spectrometry | Rtx^®^-5 amine, 30 m × 0.25 mm, 1.0-µm film (Restek Corporation, Bellefonte, PA) | Helium at 2.5 psi head pressure | 35°C for 3 minutes, then 3°C/minute to 45°C, then 25°C/minute to 175°C, held for 2 minutes
System D
Flame ionization | Rtx^®^-5 amine, 15 m × 0.53 mm, 3.0-µm film (Restek Corporation) | Nitrogen at 14 mL/minute | Isothermal at 60°C
System E
Flame ionization | PTA-5, 30 m × 0.53 mm, 3.0-µm film (Supelco, Inc.) or Rtx^®^-5 amine, 30 m × 0.53 mm, 3.0-µm film (Restek Corporation) | Helium at 4 psi head pressure | 40°C for 1 minute, then 5°C/minute to 100°C, held for 1 minute
System F
Flame ionization | PTA-5, 30 m × 0.53 mm, 3.0-µm film (Supelco, Inc.) | Helium at 4 psi head pressure | 35°C for 3 minutes, then 3°C/minute to 70°C, then 15°C/minute to 150°C, held for 2 minutes
System G
Flame ionization | DB^™^-WAX, 30 m × 0.53 mm, 1.0-µm film (J&W Scientific, Folsom, CA) | Helium at 3 psi head pressure | 35°C for 3 minutes, then 3°C/minute to 75°C, then 7°C/minute to 260°C

^a^ The gas chromatographs were manufactured by Hewlett-Packard, Inc. (Palo Alto, CA).

Table F-2 Summary of Chamber Concentrations in the Two-week Inhalation Studies of Triethylamine

| Target Concentration (ppm) | Total Number of Readings | Average Concentration^a^ (ppm)
Rat Chambers
| 100 | 218 | 101 ± 2
| 200 | 221 | 201 ± 2
| 400 | 222 | 399 ± 6
| 800 | 20 | 817 ± 5
| 1,000 | 20 | 1,009 ± 8
Mouse Chambers
| 100 | 237 | 101 ± 2
| 200 | 241 | 201 ± 2
| 400 | 242 | 400 ± 6
| 800 | 167 | 802 ± 14
| 1,000 | 168 | 988 ± 16

^a^ Mean ± standard deviation.

Table F-3 Summary of Chamber Concentrations in the Three-month Inhalation Studies of Triethylamine

| Target Concentration (ppm) | Total Number of Readings | Average Concentration^a^ (ppm)
Rat Chambers
| 12.5 | 1,285 | 12.5 ± 0.3
| 25 | 1,302 | 25.1 ± 0.5
| 50 | 1,332 | 50.2 ± 0.9
| 100 | 1,332 | 99.9 ± 2.1
| 200 | 1,333 | 201 ± 4
Mouse Chambers
| 12.5 | 1,322 | 12.5 ± 0.3
| 25 | 1,339 | 25.1 ± 0.5
| 50 | 1,371 | 50.3 ± 0.9
| 100 | 1,372 | 99.9 ± 2.1
| 200 | 1,373 | 201 ± 4

^a^ Mean ± standard deviation.

Figure F-1

Infrared Absorption Spectrum of Triethylamine

Figure F-2

Proton Nuclear Magnetic Resonance Spectrum of Triethylamine

Figure F-3

Low Resolution Mass Spectrum of Triethylamine

Figure F-4

Schematic of the Vapor Generation and Delivery System in the Inhalation Studies of Triethylamine